# APPENDIX G INTERVENTION COMPLEXITY: ICAT SYSTEMATIC REVIEW DETERMINATIONS

## 1 Baker, 2018^32^

Brief Study Description
This manuscript describes a program evaluation of St. Paul’s center of New York, Inc. which was an independent community mental health center from 2003-2012 run by psychiatric/mental health nurse practitioners caring for adults experiencing homelessness and mental illness who were not actively using substances. Program was funded by non-profit grants. It was staffed by 5 full-time NPs and a full-time office manager with back-up from an off-site psychiatrist and psychiatric clinical nurse specialist. Linkage to primary care was via a “robust referral system at major health care institutions”.; Primary outcome = Not clearly stated, but outcomes included number of patients housed, hospitalization rate, incarceration rate; Setting = New York City, U.S.
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component and delivered as a bundle | Program activities described to include multiple simultaneous and coordinated intervention components including, assessment and referral for comorbid illnesses related to chronic mental illness, individual supportive therapy, regular contact and follow up for medical screenings and referrals to primary care as needed.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Program behaviors not explicitly described but can be expected to include patient level behaviors including medication adherence, engagement with therapy, attending appointments among others.
3. Organizational levels targeted by the intervention | Multi-level | Program activities describe patient level (individual treatment), staff level (continuing education, training of new psychiatric nurse practitioners), and system level work (working with state assembly on relevant policy issues)
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly/tailored | Program offerings are stable across patients, but specific care delivered by intervention is tailored to individual patient needs
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | Basic skills | Program noted to be founded on principle that psychiatric/mental health NPs “can deliver high-quality services in an efficient manner and provide a model for systemic change in caring for homeless and disenfranchised mentally ill people”. No specific training described.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Basic skills | Patients receiving care within this program do not need specific training or skills to receive care.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | Moderate interaction | In this program, there is some interaction between professionals delivering care but no clear evidence that one would impact another.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Moderately context dependent | Programs ability to refer patients to needed services is dependent on local availability. As program is set in a large metropolitan city in the U.S., the same resources may not be available in other locations.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Highly-dependent on individual-level factors | The effect of this program would be expected to vary depending on the individual patient’s severity of mental health symptoms and readiness to engagement with care provision.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway variable, long | Causal pathway not clearly described but is expected to require multiple steps and behaviors for patients to remain successful housed, outside the hospital and criminal justice system.

## 2 Corrigan, 2017^29,33^

Brief Study Description
A 12-month, randomized controlled trial (n=67) comparing a community-based participatory research informed peer navigator program to treatment as usual for African-Americans with SMI who were experiencing homelessness. Peer navigators worked with individuals through providing patient-centered support to achieve patient identified health goals including linking them with health care providers with the overarching objective of improving psychiatric and physical health leading to improved recovery and quality of life. Usual care was treatment through the Together for Health System which was a coordinated care system including a network of more than 30 physical and mental health providers.; Primary outcome = not specified; outcome measures include physical and mental health status, recovery, quality of life, and scheduled/achieved appointments; Setting = Chicago, IL, USA
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component | Peer navigators work with patient guided by 6 fundamental approaches (eg, proactive, broad focused, active listener, shared decision-making, and problem focused). Activities guided by patient identified goals which suggested multiple aspects of support delivered together.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Because peer navigator support is directed by the patient, there is the potential for multi-targeted behaviors.
3. Organizational levels targeted by the intervention | Single | Intervention focused on patients alone.
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly tailored/flexible | Peer navigator accommodates needs and goals of individual patient.
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | High level skills | Peers are individuals with a history of experiences of homelessness and in recovery from SMI. Training includes seven 3-hour days initially, three 3-hour didactics during transition, one afternoon per week for 6 weeks for 3-hour didactic during start-up, and one afternoon per month every other month of in-service once started.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Basic skills | No specific skills required of patient receiving services.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | High level interaction | All components delivered by the peer navigator and would depend on peer navigators experience with the individual patient needs.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Highly context dependent | Effects of navigation would depend on local resources available for individual patients.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Highly dependent on individual-level factors | Effect of navigation would depend, in part, on the physical and mental health status, circumstantial social situations, and other needs of the individual patient. In addition, effectiveness of the navigation would also depend on the navigator themselves and the connection between peers.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway linear, long | While not explicitly described, it is expected that there would be multiple steps involved between peer navigation and outcomes of interest.

## 3 Kelly, 2018^31^

Brief Study Description
A randomized pilot study designed to assess the feasibility of adapting an existing peer navigator intervention to work with a mentally ill population with experiences of homelessness around the use of a collaborative electronic personal health record.; Primary outcome = feasibility appears to be the primary outcome, other measures include intervention engagement quality measures (eg, working alliance inventory short form), health service utilization, primary care provider relationship, health screening, pain, health care self-management, # log-ins into collaborative electronic personal health record.; Setting = Los Angeles, CA
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | Multi-component | Participants received coaching and instruction from health navigators around use of a collaborative electronic health record.
2. Behavior or actions of interventions recipients to which intervention is directed | Single target | Participant behavior targeted was use of the collaborative electronic health record with and without the health navigator.
3. Organizational levels targeted by the intervention | Single category | Participants were the only target of the intervention.
4. The degree of tailoring intended or flexibility permitted across individuals or sites in applying or implementing the intervention | Inflexible | All participants were expected to use the collaborative electronic health record.
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | High level skills | Health navigators had previously completed a 4-day manualized training, biweekly group supervision, and coaching around first consumer interaction. Previous training culminated in certification as health navigator. Navigators also completed 1-4 additional training sessions with the study principal investigator around tablet use and the electronic medical record.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Intermediate level skills | Individuals participating in study were required to have used the internet in the prior year “to ensure that they had some familiarity with technology”.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | Independent | Intervention has only one component.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Highly context dependent | Intervention requires access to a unique collaborative electronic health record system which leverages existing technology to make; it patient accessible and which is not universally available.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Moderately; dependent on; individual level factors | A participant’s ability to engage with collaborative health record is likely dependent on their current symptom status of their serious mental illness and other comorbidities.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Unable to assess | Insufficient information provided.

## 4 McGuire, 2009^37^

Brief Study Description
This is a pre-post study of an intervention (“integrated care”) offered through a demonstration primary care clinic that integrates homeless, primary care, and mental health services for homeless veterans with SMI or substance abuse offered in VA. The demonstration clinic co-locates primary care, MH care, and homeless services in a Mental Health Outpatient Treatment Center (MHOTC funded by VA Central Office). Veterans with usual care primary care services (received before demonstration clinic opened) are compared to those who received care in the demonstration clinic (post-integration group); Primary outcome = use of emergency services, physical health status, use of primary care services; Setting = LA VA
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component and provided as a bundle | Veterans were evaluated in a screening clinic and referred to all needed services within the MHOTC building. Goal was for Veteran to have a primary care visit on the same day as the screening visit. Team used weekly case conferences, building operation meetings, SOPs, and policies to facilitate interclinic coordination and communication.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Intervention sought to address mental health, primary health, housing needs and other support (ie, transportation) needs.
3. Organizational levels targeted by the intervention | Multi-level | Intervention targets mentally ill Veterans with experiences of homelessness and how these services are offered within the LA VA system in an integrated way. While primary care model was similar, services were co-located and additional standard operating procedures were put in place to facilitate communication between MH, primary care, and homeless service teams.
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly tailored/flexible | Model of care is stable across patients, but specific care delivered by intervention is tailored to individual patient needs
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | Intermediate level skills | Primary care providers received training on Healthcare for the Homeless including infectious disease screening and treatment, chronic pain, and hypertension management.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Basic skills | Patients receiving care within this model do not need specific training or skills to receive care.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | High level of interaction | This model of care is designed to be highly interactive and service needs are determined through an initial comprehensive assessment and immediate referral to primary care. Case managers are involved and teams meet regularly to discuss cases.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Moderately context dependent | The approach could be generalized across VAs particularly if VA central office provided funded for other similar clinics. All VAs offer homeless services and have provide similar levels of primary and mental health care and VA has been a pioneer in thinking about integrated care.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Highly dependent on individual-level factors | The effect of this care model would be expected to vary depending on the individual patient’s severity of mental health symptoms and readiness to engage with care provision.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway linear, long | One of the outcomes is improved access to primary care which could be achieved through the immediate primary care visit that is scheduled on the same day as the screening. However, other outcomes, including use of ED services and improved health would likely require additional primary care and MH visits and housing support to achieve though the immediate link with primary care makes that link more straight forward.

## 5 Patterson, 2012^47^

Brief Study Description
An interagency collaboration, British Columbia’s Homeless Intervention Project (HIP), provided coordinated housing and support services to adults with serious mental illness and who chronically experience homelessness. The project brought a “variety of health, social and housing resources from diverse government and non-profit agencies” under a single administrative organization and service providers from multiple agencies were co-located. This analysis collected data from the HIP program at 3 provincial ministries.; Primary outcome = primary goals of program stated as increasing use of primary care, decreasing the number of hospitalizations and length of stay, decreasing justice system involvement, and increasing the use of income assistance.; Setting = British Columbia, Canada
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component | Multiple agencies involved in project; however, limited detail is provided with which to determineif components are delivered as a bundle.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Behaviors/actions of this project are directed at the agency and clinician levels. Though not explicitly described, since the provision of care to the target population is expected to be complex, the behaviors targeted in delivering such care are expected to be multi-targeted.
3. Organizational levels targeted by the intervention | Multi-level | Project appears to impact agencies and individual clinicians that deliver care to this population.
4. The degree of tailoring intended or flexibility permitted across individuals or sites in applying or implementing the intervention | Moderately; tailored/flexible | Project noted to include a “common monitoring framework to ensure fidelity and standardization of activities across sites.”
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | Unable to assess | Insufficient information provided.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Intermediate skills | Skills of clinicians and agencies appear to be standard for given profession.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | Unable to assess | Insufficient information provided.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Moderately context dependent | While this intervention was implemented at multiple sites within British Columbia, there is little information provided about differences across sites. However, it can be expected that while this intervention would depend on locally available personnel and resource availability and the specific health policy and financial resources found in British Columbia.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Moderately dependent on individual level factors | Differences in resources and personnel across agencies could be expected to impact effect of interagency collaboration.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Unable to assess | Insufficient information provided.

## 6 Rivas-Vazquez, 2009^36^

Brief Study Description
This study uses a non-randomized control pre/post comparison to assess the effectiveness of a post-booking jail diversion program that ensured access to psychiatric and primary health care for a homeless program for a population experiencing homelessness with mental illness. Individuals in “relationship-based care” program were compared to individuals diverted to usual care (other programs otherwise non-specified in the community).; Primary outcome = rate of arrests after admission to program; Setting = South Florida
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component and provided as a bundle | Intervention included outreach team, comprehensive assessment, advocate at hearing, and primary and psychiatric care and housing support. Also provided with health education and other support as needed.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Intervention sought to address material, health, and legal needs in order to reduce criminal recidivism.
3. Organizational levels targeted by the intervention | Multi-level | Intervention targets populations who experience homelessness and mental illness in need of a jail diversion program. Sought to turn CHC services into jail diversion program, trained outreach team.
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly tailored/flexible | Model of care is stable across patients, but specific care delivered by intervention is tailored to individual patient needs
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | High level skills | Paper did not talk much about steps taken to ensure coordinated care within CHC, but there was a specialized outreach team and inclusion of legal support.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Basic skills | Patients receiving care within this model do not need specific training or skills to receive care.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | High level of interaction | This model of care is designed to be highly interactive along a continuum from release from jail to integration in the community. A trained outreach team engages individuals who will be released from jail, they conduct a comprehensive assessment and services from various sectors come together to meet the patient’s health, legal, case management, housing, and other support needs.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Highly context dependent | The underlying approach could be generalized, but in this case, the CHC received external funding to implement this intervention and there were clear champions within the judicial system that facilitated the environment within which this intervention could occur.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Highly dependent on individual-level factors | The effect of this care model would be expected to vary depending on the individual patient’s severity of mental health symptoms and readiness to engagement with care provision.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway variable, long | While no clear causal pathway is outlined or theory provided to understand potential causal pathway, the intervention involves so many factors that it is likely that the intervention could operate through multiple pathways and interactions between services and the patients’ mental health function and willingness to engage.

## 7 Rosenheck, 1993^45^

Brief Study Description
A VA-based program started in 1987 called the VA Homeless Chronically Mentally Ill (HCMI) designed to support access of Veterans with housing insecurity and chronic mental illness with medical and psychiatric services through four key services: outreach, advocacy and linkage, facilitation of access to VA and non-VA services, residential treatment for up to 6 months, and continuing case management. Sites are each staffed by two clinicians (mostly social workers and nurses).; Primary outcome = utilization and cost of VA health services; Setting = nine program sites within the larger national Veterans Affairs Health Care System program; n=1,748 patients
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component and delivered as a bundle | Limited description, however, four key services outlined would require multiple components to be delivered together
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Limited description, however, would anticipate that patients would need to exhibit multiple behaviors to engage with each of the four key services.
3. Organizational levels targeted by the intervention | Single category | This intervention is directed at the patient recipients.
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly tailored | The extent to which each patient receives the key services would be tailored to their need.
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | Basic skills | No evidence that administrators of the program would need additional training.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Basic skills | No evidence that recipients of the program would need additional training beyond standard professional training though primarily delivered by master’s level social workers and nurses.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | High level interaction | Integration of multiple key services are expected to require a high level of complex interdependence.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Moderately context dependent | Specific program offerings likely somewhat variable across 43 VA sites, however, functioning within a national health care system.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Highly dependent on individual level factors | A participant’s ability to engage with the care offered is likely dependent on their current symptom status of their serious mental illness and other comorbidities.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway variable, long | While not specifically articulated, the causal pathway is expected to be complex with multiple steps required for an individual patient to engage with programmatic offerings to have improved health, and stable housing.

## 8 Solomon, 1988^48^

Brief Study Description
This program evaluation of a demonstration project is based on an adjunctive program to an existing Health Care for the Homeless project which delivered primary health care services, service linkage, and improved access to population specific public benefits and programs. The adjunctive mental health program was intended to establish drop-in centers and provide outreach, assessment, and case management services for participants and educational, training programs and crisis back-up for non-mental health providers caring for this population.; n=NR; Primary outcome=not identified; included both process and summative evaluation; Setting=Cleveland, OH
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component and delivered as a bundle | Multiple components delivered as bundles to patients and non-mental health staff.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Limited description, however engaging in care with both medical and mental health care would require multiple behaviors; in addition, caring for patients with both serious mental illness and a history of housing insecurity would require multiple actions.
3. Organizational levels targeted by the intervention | Multi-category | Program is directed at both patient participants and non-mental health providers.
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly tailored | Limited description, however, the extent to which each patient receives the key services is assumed to be tailored to individual need; similarly, educational training likely was designed to meet the needs of providers across settings (eg, shelters vs meal-site).
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | Intermediate level skills | Some skills around collaboration and integration in a specialized clinical team are expected, as well as expertise to provide educational training.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Intermediate skills | No specific skills required for patient participants; however, providers would be required to have their basic professional training.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | High level interaction | It is expected that the various intervention components provided to patients are internally interdependent and interact with the training provided to non-mental health providers.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Highly context dependent | The described program was initiated as an adjunct to an existing program to provide health care for individuals experiencing homelessness.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Highly dependent on individual level factors | A patient participant’s ability to engage with integrated care is likely dependent on their current symptom status of their serious mental illness and other comorbidities. Provider factors are expected to be less dependent on individual factors.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway variable, long | While not specifically articulated, the causal pathway is expected to be complex with multiple steps required for an individual patient to engage with programmatic offerings to have improved health, and stable housing.

## 9 Stanhope, 2014^30^

Brief Study Description
This is a qualitative study exploring the experience of patients with axis I diagnoses of SMI and housing insecurity participating in a Housing-First program based chronic disease self-management program from the Stanford Chronic Disease Self-management program (CDSMP). The program involved the integration of an embedded primary care physician affiliated with a local academic medical center.; Primary outcome = “barriers and facilitators to addressing health care needs of people enrolled in a chronic disease self-management program within a supported housing program”; Setting = US (city not reported)
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component and delivered as a bundle | Minimal information available, however, participants received integrated primary care and an established multi-component chronic disease self-management program in conjunction with other supports inherent in the interdisciplinary housing first program.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Behaviors expected of program participants are not explicitly described but can be expected to include patient level behaviors including medication adherence, engagement with therapy, self-management behaviors which are almost always multi-faceted, and attending appointments among others.
3. Organizational levels targeted by the intervention | Single category | This intervention is directed at the patient recipients.
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly tailored/flexible | While program components are universally available to participants who opt into the chronic self-management program, the combination and intensity of individual components will be uniquely customized to the needs of the individual participant.
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | High skill level | Individuals (peer educators/facilitators) delivering the chronic self-management program were brought in specifically to deliver the 6-week program as they had previously conducted the program at a similar location.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Basic skills | No special experience required for participants of the program.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | High level interaction | It can be expected that acquisition of selfmanagement skills would have a synergistic effect on primary care provision in an interdisciplinary context.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Highly context dependent | Ability to recreate the interdisciplinary team would require access to similar personnel through local academic medical centers. In addition, conducting the described program would require local expertise for delivery.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Moderately dependent on individual level factors | A participant’s ability to engage with the care offered is likely dependent on their current symptom status of their serious mental illness and other comorbidities.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway variable, long | While not specifically articulated, the causal pathway is expected to be complex with multiple steps required for an individual participant and that one participant’s path towards improved health, disease selfmanagement, and stable housing could look different from another participant.

## 10 Stergiopoulos, 2012^49^

Brief Study Description
This manuscript describes the evaluation of a novel Housing First Ethno-Racial Intensive Case; Management program which was funded as part of the Mental health Commission of Canada’s At; Home/Chez Soi Research Demonstration Project across 5 Canadian Cities (Moncton, Montreal, Toronto, Winnipeg, and Vancouver). The program involved housing support and diverse programming including services such as art therapy, computer training and yoga. n=204 (intervention=102; control=102); Primary outcome=not stated as such but included recruitment, fidelity, program provider and participants perspectives, implementation challenges and facilitators; Setting=Toronto, Canada
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component and delivered as a bundle | Multiple components of care including case management and other support services delivered together to patients.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Limited description, however engaging in care with both medical and mental health care would require multiple behaviors.
3. Organizational levels targeted by the intervention | Single category | Services provided by program are directed at patient participants.
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly tailored | Limited description, however, the extent to which each patient receives the key services is assumed to be tailored to individual need.
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | High level skills | To achieve stated goals of focus on antiracism and anti-oppression care delivery, the program partnered with a skilled and experienced agency to lead and implement the service model (ie, Across Boundaries).
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Intermediate skills | Patient participants were not required to have specific skills per se, however, had to agree to weekly face-to-face meetings with their case manager and a limit was placed on proportion of income used for rent.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | High level interaction | Given that care is integrated, it is expected; that components of program are interdependent.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Moderately context dependent | Larger program of which this was a component took place in multiple cities across Canada, though this one was only in Toronto and appears to rely on local expertise and is tailored to a specific multiracial/cultural population.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Highly dependent on individual level factors | A patient participant’s ability to engage with integrated care is likely dependent on their current symptom status of their serious mental illness and other comorbidities.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway variable, long | While not specifically articulated, the causal pathway is expected to be complex with multiple steps required for an individual patient to engage with programmatic offerings to have improved health, and stable housing.

## 11 Stergiopoulos, 2015^34^

Brief Study Description
A quasi-experimental study comparing outcomes of two shelter-based collaborative mental health care models for men experiencing homelessness and mental illness. One model was an integrated multidisciplinary collaborative care model (IMCC) and the second was a less resource intensive shifted outpatient collaborative care model (SOCC). IMCC is a 780-bed shelter that partners with local teaching hospital to provide onsite psychiatrist or mental health worker 4 half days per week as an integrated member of primary care team. SOCC is a 480-bed shelter has a psychiatric consultant who is not administratively linked to primary care but who provides outpatient treatment one half day per week in shelter. SOCC does not provide on-site primary care, but patients are referred to neighboring primary care clinics.; Primary outcome = patient’s level of community functioning 12 months after study enrollment; Setting = Toronto, Ontario
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | IMCC: more than one component and delivered as a bundle; SOCC: more than one component | IMCC: This model of care offers interdisciplinary stepped care with intentional communication among professionals of diverse backgrounds with an emphasis on coordinated care and integrated shelter-based care and case management. A common electronic medical record is used.; SOCC: In this model of care, primary care and nursing is not offered on site and communication is limited to the psychiatrist and “select shelter staff.” There is no integration between primary care and mental health and primary care is accessed via referral to near-by primary care clinics.
2. Behavior or actions of interventions recipients to which intervention is directed | IMCC: Multi-target; SOCC: Multi-target | IMCC: Intervention (model of care) is delivered to men with mental health disorders and who are experiencing homelessness. While not explicitly described, patients are interacting with staff members of multiple disciplines (medicine, housing services, mental health) which will be addressing separate patient-level behaviors; SOCC: same as above
3. Organizational levels targeted by the intervention | IMCC: Single category; SOCC: Single category | IMCC: Intervention (model of care) targets men experiencing homelessness with mental illness who are accessing shelter.; SOCC: Intervention (model of care) targets men experiencing homelessness with mental illness who are accessing shelter.
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | IMCC: Highly tailored/flexible; SOCC: Highly tailored/flexible | IMCC: Model of care is stable across patients, but specific care delivered by intervention is tailored to individual patient needs. Flexible entry into program and accessing needed services.; SOCC: same as above
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | IMCC: Intermediate level skills; SOCC: Basic skills | IMCC: In addition to professional training, members of integrated model must demonstrate purposeful, integrated collaboration.; SOCC: In this model, professionals are delivering care in manner standard to their professional training.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | IMCC: Basic skills; SOCC: Basic skills | IMCC: Patients receiving care within this model do not need specific training or skills to receive care.; SOCC: same as above
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | IMCC: High level of; interaction; SOCC: Moderate interaction | IMCC: As this model of care is designed to be integrative and collaborative, the actions of each team member impact the actions of others; successful care delivery of individual team members can be expected to increase the likelihood of successful care delivered by others.; SOCC: In this model of care, there is some interaction between professionals delivering care but no clear evidence that one would impact another.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | IMCC: Moderately context dependent; SOCC: Highly context dependent | IMCC: Care delivered by this model of care is largely internally contained and thus less dependent on availability of clinical resources outside the specific shelter. However, healthcare policies and structures may differ significantly outside of Canada which would impact implementation.; SOCC: As care delivered by this alternate model depends on referrals to neighboring clinics to provide core services (ie, primary care), implementation of this program would be highly dependent on the context. Geographic context principles apply to this model as well.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | IMCC: Highlydependent on individuallevel factors; SOCC: Highlydependent on individuallevel factors | IMCC: The effect of this care model would be expected to vary depending on the individual patient’s severity of mental health symptoms and readiness to engagement with care provision.; SOCC: same as above
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | IMCC: Pathway variable, long; SOCC: Pathway variable, long | IMCC: While no clear causal pathway is outlined, the course from entry into care to primary outcome (ie, level of community functioning at 12 month) is expected to be variable with multiple steps required.; SOCC: same as above

## 12 Stergiopoulos, 2018^28^

Brief Study Description
This manuscript and its associated protocol paper (Stergiopoulos et al, 2017) describe a pre-post mixed method study to evaluate a brief (4-6 month) interdisciplinary intervention (Coordinated Access to Care for the Homeless or CATCH program) for adults experiencing homelessness who lack access to appropriate community supports following discharge from the hospital. CATCH is described as a “one-stop” program that includes primary and psychiatric care, peer support and case management for individuals discharged from the hospital. The program features a weekly “low barriers” clinic staffed with a nurse, a primary care physician and two psychiatrists. Clinic staff work “seamlessly” with case managers on multidisciplinary assessments and comprehensive plans. Other features include outreach, crisis intervention, assistance with material supports, and interagency partnerships with local hospitals.; Primary outcome = change in participant health status from baseline to 6 months as evaluated by the physical and mental health component scores of the Short-Form 36 (SFS-36); Setting = Toronto, Canada
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component and delivered as a bundle | Intervention activities include multiple simultaneous and coordinated intervention components including, assertive outreach, crisis intervention, assistance with material supports, and primary and mental health care provision.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Behaviors targeted by the intervention are not explicitly described but can be expected to include patient level behaviors including medication adherence, engagement with therapy and medical care, and executive tasks such as applying for financial and housing resources.
3. Organizational levels targeted by the intervention | Single category | Intervention is directed at adults experiencing homelessness with unmet physical or mental needs as identified by clinicians and unmet support needs as identified by patient.
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly/tailored | Intervention offerings are stable across patients, but specific care delivered by intervention is tailored to individual patient needs.
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | Intermediate level skills | Training of intervention staff not explicitly described but could expect some skill needed to achieve level of described multidisciplinary coordination.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Basic skills | Participants receiving care within this program do not need specific training or skills to receive care.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | High level interaction | The design of this intervention is described as interdisciplinary and includes multiple opportunities for care delivery interaction in a manner that is expected to be synergistic.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Moderately context dependent | It can be expected that while this intervention as described is largely selfcontained, the ability to implement it would depend on locally available personnel and resource availability and the limitations of health policy and financial resources.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Highly-dependent on individual-level factors | The effect of this intervention would be expected to vary depending on the individual patient’s severity of mental health symptoms and readiness to engagement with care provision.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway variable, long | Causal pathway not clearly described but is expected to require multiple steps and behaviors for patients to achieve better physical and mental health status.

## 13 Weinstein, 2013^46^

Brief Study Description
This program evaluation describes a Housing First Program started in 2008 and affiliated with an academic medical center with a subgroup of patients who opted to receive “fully integrated care by the on-site primary care physician and team psychiatrist”. Primary care was available 2 half-days per week. All program participants received on-site psychiatry and nursing care. A stated focus of the integrated care program was to screen and monitor chronic disease.; n=123 participants; 43 integrated care subgroup; Primary outcome=healthcare quality indicators from National Association of State Mental health Program Directors (NASMHPD) and Healthcare Effectiveness Data Information Set (HEDIS); Setting=Philadelphia, PA
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component and delivered as a bundle | Limited description, however, fully integrated care from at least three disciplines (medicine, psychiatry, nursing) implies multiple components administered together.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Limited description, however engaging in care with both chronic disease and mental health care would require multiple behaviors
3. Organizational levels targeted by the intervention | Single category | Services of program are provided to patients.
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly tailored | Limited description, however, the extent to which each patient receives the key services is assumed to be tailored to individual need.
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | Intermediate level skills | Limited description, however, some skills around collaboration and integration in a specialized clinical team are expected.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Basic skills | No special skills are noted for patients receiving care through this program.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | High level interaction | Given that care is integrated, it is expected that components of program are interdependent.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Moderately context dependent | It is expected that program offerings and available collaborations could vary by location (eg, access to academic affiliate).
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Highly dependent on individual level factors | A participant’s ability to engage with integrated care is likely dependent on their current symptom status of their serious mental illness and other comorbidities.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway variable, long | While not specifically articulated, the causal pathway is expected to be complex with multiple steps required for an individual patient to engage with programmatic offerings to have improved health, and stable housing.

## 14 Weinstein, 2013^35^

Brief Study Description
This paper describes a preliminary formative evaluation of a program which created a new partnership between an academic family and community medicine department and a Housing First agency (ie, Pathways to Housing-PA) with an overarching goal of addressing multiple levels of health care needs for the target population. The program specifically embedded a primary care physician into the Housing First agency’s Assertive Community Treatment team to provide on-site “primary care and population-based health monitoring and services.”; Primary outcome = the overlap between program components and primary care medical home elements; Setting = Philadelphia, PA, US
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component and delivered as a bundle | Participants receive “fully integrated” primary and behavioral health care as a part of the program, in addition to care transitions and other supports inherent in the interdisciplinary housing first program.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Behaviors expected of program participants are not explicitly described but can be expected to include patient level behaviors including medication adherence, engagement with therapy, attending appointments among others.
3. Organizational levels targeted by the intervention | Single category | Program is directed at patient participants.
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly tailored/flexible | While program components are universally available to participants, the combination and intensity of individual component will be uniquely customized to the needs of the individual participant.
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | Intermediate level skills | Interdisciplinary team members are practicing within their established scope of practice, however, requires training for providers in “population-centric models of care.”
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Basic skills | There is not expectation that participants enter the program with previously existing skill sets.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | High level interaction | Program components are derived from care provided by interdisciplinary team which is intentionally coordinated and interdependent.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Highly context dependent | Program components are presumed to be unique to the offerings of the existing programs which were co-located and integrated. Other implementation sites may not have access to the same offerings.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Moderately dependent on individual level factors | A participant’s ability to engage with the care offered is likely dependent on their current symptom status of their serious mental illness and other comorbidities.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway variable, long | While not specifically articulated, the causal pathway is expected to be complex with multiple steps required for an individual participant and that one participants path towards improved health and stable housing could look different from another participant.

## 15 ACCESS Studies

Calloway, 1998^42^

Cheng, 2008^38^

Cocozza, 2000^41^

Morrissey, 1997^44^

Rosenheck, 1997^43^

Rosenheck, 2002^40^

Steadman, 2002^39^

Brief Study Description
A quasi-experimental federal demonstration program, Access to Community Care and Effective Strategies and Supports (ACCESS), conducted over 5 years ending in 1999 which was designed to support system change through partnership development across federal, state, local, and private service agencies for people experiencing homelessness with serious mental illness and co-occurring substance disorders. A second goal of the program was to identify effective, replicable system integration strategies. Funding (average $5 million; approximately $250,000 per site) was provided at the state level to support provision of essential services to the target population, including assertive outreach, case management (100 patients per site per year), housing, mental health, and substance abuse treatment. Per communication with an author, while the intention was that primary care would be incorporated at each site; the extent to which that happened varied.; Primary outcome = varied by article, but outcomes included continuation of services after funding ended, size of caseload, integration strategies chosen, quantification of level of implementation; extent of agency linkages; treatment outcomes; perceived needs by patient and service provider; genderspecific response to initiative; Setting = 18 US sites in 9 states (ie, Connecticut, Illinois, Kansas, Missouri, North Carolina, Pennsylvania, Texas, Virginia, and Washington); in each state identified one systems integration site and one control site (matched on demographic and economic variables)
Core Dimension | Judgment | Support for Judgment
1. Active components included in the intervention, in relation to comparison | More than one component and delivered as a bundle | The stated requirements for ACCESS participation sites were broad and did not dictate how all components of interdisciplinary and interagency care for patients experiencing homelessness with SMI were delivered. However, involvement of multiple agencies and multiple types of care delivery were expected to be provided to individual patients.
2. Behavior or actions of interventions recipients to which intervention is directed | Multi-target | Target behaviors of ACCESS program were largely directed at the providers or agencies serving the target population. Developing linkages and integration services across multiple organizations is expected to be complex and require multiple behaviors (eg, interagency communication, alignment of efforts,etc)
3. Organizational levels targeted by the intervention | Multi-level | ACCESS was designed to impact at the community level (eg, increase interagency linkages), agency/clinic level (eg, develop new clinic level resources), and patient level (eg, direct case management and outreach).
4. The degree of tailoring intended or flexibility permitted across individuals in applying or implementing the intervention | Highly tailored | Each ACCESS site developed its own approach to implemented intended domains.
5. The level of skill required by those delivering the intervention in order to meet the intervention objectives. | Intermediate level skills | ACCESS intended for existing agencies to combine efforts, so were presumably using existing skill sets though likely had to work on new skills around system integration.
6. The level of skill required for targeted behavior when entering the study by those receiving the intervention, in order to meet the intervention objectives | Basic skills | No special experience required for participants of the program.
7. The degree of interaction between intervention components, including the independence/interdependence of intervention components | High level interaction | While variable across sites, integration strategies and degree of linkages suggest that intervention components delivered by cooperating agencies would impact those delivered by another agency.
8. The degree to which the effects of the intervention are dependent on the context or setting in which it is implemented | Highly context dependent | State and city level resources and regulations as well as interests and priorities are expected to have contributed significantly to effect of the intervention.
9. The degree to which the effects of the intervention are changed by recipient or provider factors. | Highly dependent on individual level factors | A participant’s ability to engage with the care offered is likely dependent on their current symptom status of their serious mental illness and other comorbidities. Similarly, since much of the ACCESS intervention occurred at the agency level, the degree to which agencies were integrated likely depended on their ability and willingness to collaborate.
10. The nature of the causal pathway between the intervention and the outcome it is intended to effect. | Pathway variable, long | While not specifically articulated, the causal pathway is expected to be complex with multiple steps required for an individual agency to create new linkages and for participants to have improved health, and stable housing.