# APPENDIX F EXCLUDED STUDIES TABLE

| Exclusion Reason
Study | Not OECD | Not population | Not intervention | Not design
Anonymous, 2005^1^ | | X
Barrow, 2019^2^ | | X
Basu, 2012^3^ | | X
Behl-Chadha, 2017^4^ | | X
Beiser, 2019^5^ | | | X
Bennett, 1995^6^ | | X
Biederman, 2019^7^ | | X
Blue-Howells, 2008^8^ | | X
Boardman, 2006^9^ | | X
Booth, 2019^10^ | | | | X
Bottomley, 2001^11^ | | X
Bowker, 2013^12^ | | X
Bracken, 1999^13^ | | X
Brown, 2013^14^ | | X
Brown, 2018^15^ | | X
Brush, 1999^16^ | | | | X
Buck, 2011^17^ | | X
Caban-Aleman, 2020^18^ | | X
Canham, 2019^19^ | | X
Carriere, 2008^20^ | | X
Carter, 1994^21^ | | X
Center for Substance Abuse, 4734^22^ | | | | X
Chan, 2019^23^ | | X
Chhabra, 2020^24^ | | | X
Child, 1998^25^ | | X
Christensen, 2004^26^ | | | X
Chrystal, 2015^27^ | | | X
Ciaranello, 2006^28^ | | X
Clark, 2003^29^ | | | X
Clark, 1999^30^ | | | | X
Community Psychiatry Program, 1989^31^ | | | | X
Conovkr, 1997^32^ | | X
Culhane, 2002^33^ | | | X
Currie, 2018^34^ | | X
Darbyshire, 2006^35^ | | X
Dates, 2009^36^ | | | X
Davis, 2012^37^ | | | | X
Deas-Nesmith, 1992^38^ | | | | X
Dennis, 2000^39^ | | | | X
Desai, 2005^40^ | | X
Dickey, 2000^41^ | | | | X
Dickins, 2019^42^ | | X
Doering, 2002^43^ | | | X
Dorney-Smith, 2011^44^ | | X
Douglass, 2018^45^ | | X
Elissen, 2013^46^ | | X
Ellison, 2016^47^ | | | X
Essendorfer, 2007^48^ | | | X
Fernandez, 1985^49^ | | | | X
Ferreira, 2016^50^ | X
Flores, 1998^51^ | | | X
Fournier, 1993^52^ | | X
Fraino, 2015^53^ | | X
Gabrielian, 2017^54^ | | X
Gabrielian, 2016^55^ | | X
Gabrielian, 2014^56^ | | X
Gatewood, 2011^57^ | | X
Gelberg, 1996^58^ | | X
Gordon, 2007^59^ | | X
Gundlapalli, 2017^60^ | | X
Gundlapalli, 2005^61^ | | X
Gunner, 2019^62^ | | | X
Hatton, 2001^63^ | | X
Henwood, 2013^64^ | | | X
Henwood, 2011^65^ | | | | X
Hoist, 2008^66^ | | | | X
Howe, 2009^67^ | | X
Jego, 2018^68^ | | | X
Jego, 2016^69^ | | X
Johnson, 2017^70^ | | X
Jones, 2017^71^ | | | X
Jones, 2018^72^ | | X
Kaduszkiewicz, 2017^73^ | | | X
Kalton, 2016^74^ | | X
Kaplan-Weisman, 2019^75^ | | X
Keogh, 2015^76^ | | X
Kerman, 2016^77^ | | | X
Kertesz, 2013^78^ | | X
Kertesz, 2009^79^ | | X
Kessell, 2006^80^ | | X
Kirkland-Kyhn, 2020^81^ | | | | X
Koh, 2016^82^ | | | | X
Koon, 2010^83^ | | X
Kuehn, 2019^84^ | | | | X
Lam, 1999^85^ | | | X
Lamanna, 2018^86^ | | X
Lashley, 2019^87^ | | X
Lee, 2013^88^ | | X
Levy, 2004^89^ | | | | X
Liu, 2020^90^ | | X
Luchenski, 2018^91^ | | X
Madrid, 2008^92^ | | X
Marshall, 1995^93^ | | | X
McGuire, 2007^94^ | | | X
McGuire, 2004^95^ | | | X
McGuire, 2002^96^ | | X
McInnes, 2014^97^ | | X
Mehta, 2017^98^ | | X
Mercuel, 2013^99^ | | | X
Mishan, 2017^100^ | | X
Montgomery, 2008^101^ | | | X
Moore, 2017^102^ | | X
Moore, 2019^103^ | | X
Morrissey, 2002^104^ | | | X
Morse, 1997^105^ | | | X
Mowbray, 1992^106^ | | X
Myers, 2018^107^ | | X
Nakashima, 2004^108^ | | X
Nakonezny, 2005^109^ | | X
Ng, 2004^110^ | | X
No authorship, 1986^111^ | | | | X
O’Toole, 2013^112^ | | X
O’Toole, 2010^113^ | | X
O’Toole, 2016^114^ | | X
O’Toole, 2015^115^ | | X
O’Toole, 2018^116^ | | X
O’Toole, 2011^117^ | | X
Parker, 2019^118^ | | | X
Paudyal, 2018^119^ | | X
Pauly, 2018^120^ | | X
Pfeil, 2004^121^ | | X
Pickett, 2015^122^ | | X
Podymow, 2006^123^ | | X
Pollio, 2000^124^ | | | X
Purkey, 2019^125^ | | | X
Putnam, 1985^126^ | | | | X
Raines, 2019^127^ | | | | X
Resnik, 2017^128^ | | X
Rogers, 1993^129^ | | | | X
Rosenbaum, 2017^130^ | | | X
Rosenheck, 1995^131^ | | X
Rosenheck, 1997^132^ | | | X
Rosenheck, 1998^133^ | | | X
Rothbard, 2004^134^ | | | X
Rowe, 2016^135^ | | X
Salize, 2013^136^ | | X
Sarango, 2017^137^ | | X
Sestito, 2017^138^ | | X
Shepherd, 1998^139^ | | X
Shortt, 2008^140^ | | X
Simmons, 2017^141^ | | | | X
Smelson, 2018^142^ | | | X
Snyder, 2002^143^ | | X
Stein, 2000^144^ | | X
Stergiopoulos, 2015^145^ | | | X
Strange, 2018^146^ | | X
Sumalinog, 2017^147^ | | | | X
Summerside, 2013^148^ | | X
Swabri, 2019^149^ | | X
Timms, 2016^150^ | | | X
Tollett, 1995^151^ | | X
Trabert, 2016^152^ | | | | X
Tsai, 2019^153^ | | X
Tyner, 2014^154^ | | | | X
Upshur, 2017^155^ | | | X
Vargas, 2018^156^ | X
Vazquez Souza, 2011^157^ | | | X
Vickery, 2020^158^ | | X
Weinreb, 2007^159^ | | X
Wenger, 2007^160^ | | | | X
Wijk, 2019^161^ | X
Wilkins, 2015^162^ | | | | X
Worley, 1990^163^ | | X
Wright, 2016^164^ | | X
Wright, 2004^165^ | | X
Zerger, 2009^166^ | | X
Zlotnick, 2013^167^ | | X

## Excluded Studies Reference List

1 Anonymous. Discharge planning advisor. Innovative program helps homeless, frees up beds. Hosp Case Manag. 2005;13(10):155–157.16218549
2 Barrow V, Medcalf P. The introduction of a homeless healthcare team in hospital improves staff knowledge and attitudes towards homeless patients. Clin Med (Northfield Il). 2019;19(4):294–298.
3 Basu A, Kee R, Buchanan D, Sadowski LS. Comparative cost analysis of housing and case management program for chronically ill homeless adults compared to usual care. Health Serv Res. 2012;47(1 Pt 2):523–543.22098257
4 Behl-Chadha B, Savageau JA, Bharel M, Gagnon M, Lei PP, Hillerns C. Comparison of Patient Experience between a Practice for Homeless Patients and Other Practices Engaged in a Patient-Centered Medical Home Initiative. J Health Care Poor Underserved. 2017;28(3):1151–1164.28804084
5 Beiser ME, Smith K, Ingemi M, Mulligan E, Baggett TP. Hepatitis C treatment outcomes among homeless-experienced individuals at a community health centre in Boston. International Journal of Drug Policy. 2019;72:129–137.30962036
6 Bennett JB, Scholler-Jaquish A. The winner’s group: a self-help group for homeless chemically dependent persons. J Psychosoc Nurs Ment Health Serv. 1995;33(4):14–19.
7 Biederman DJ, Gamble J, Wilson S, Douglas C, Feigal J. Health care utilization following a homeless medical respite pilot program. Public Health Nurs. 2019;36(3):296–302.30746762
8 Blue-Howells J, McGuire J, Nakashima J. Co-location of health care services for homeless veterans: a case study of innovation in program implementation. Soc Work Health Care. 2008;47(3):219–231.19042482
9 Boardman JB. Health access and integration for adults with serious and persistent mental illness. Families, Systems and Health. 2006;24(1):3–18.
10 Booth A, Preston L, Baxter S, Wong R, Chambers D, Turner J. NIHR Journals Library. Health Services and Delivery Research. 2019;9:9.
11 Bottomley JM. Health care and homeless older adults. Topics in Geriatric Rehabilitation. 2001;17(1):1–21.
12 Bowker D, Weg B, Hansen E. Nontraditional clinical sites: working with those who are homeless. Nurse Educ. 2013;38(4):139–140.23778038
13 Bracken P, Cohen B. Home treatment in Bradford. Psychiatric Bulletin. 1999;23(6):349–352.
14 Brown CA, Hickey JS, Buck DS. Shaping the Jail Inreach Project: program evaluation as a quality improvement measure to inform programmatic decision making and improve outcomes. J Health Care Poor Underserved. 2013;24(2):435–443.23728020
15 Brown M, Rowe M, Cunningham A, Ponce AN. Evaluation of a Comprehensive SAMHSA Service Program for Individuals Experiencing Chronic Homelessness. The journal of behavioral health services & research. 2018;45(4):605–613.29435863
16 Brush BL, McGee EM. The Expanded Care for Healthy Outcomes (ECHO) Project: addressing the spiritual care needs of homeless men in recovery. Clin Excell Nurse Pract. 1999;3(2):116–122.10646400
17 Buck DS, Brown CA, Hickey JS. The Jail Inreach Project: linking homeless inmates who have mental illness with community health services. Psychiatr Serv. 2011;62(2):120–122.21285087
18 Caban-Aleman C, Iobst S, Luna AM, Foster A. Addressing the Poverty Barrier in Collaborative Care for Adults Experiencing Homelessness: A Case-Based Report. Community Ment Health J. 2020;56(4):652–661.31907804
19 Canham SL, Davidson S, Custodio K, . Health supports needed for homeless persons transitioning from hospitals. Health & Social Care in the Community. 2019;27(3):531–545.30011102
20 Carriere GL. Linking women to health and wellness: Street Outreach takes a population health approach. International Journal of Drug Policy. 2008;19(3):205–210.18468879
21 Carter KF, Green RD, Green L, Dufour LT. Health needs of homeless clients accessing nursing care at a free clinic. J Community Health Nurs. 1994;11(3):139–147.7964933
22 Center for Substance Abuse T. Substance Abuse and Mental Health Services Administration. 4734.
23 Chan B, Hulen E, Edwards S, Mitchell M, Nicolaidis C, Saha S. “It’s Like Riding Out the Chaos”: Caring for Socially Complex Patients in an Ambulatory Intensive Care Unit (A-ICU). Ann Fam Med. 2019;17(6):495–501.31712287
24 Chhabra M, Spector E, Demuynck S, Wiest D, Buckley L, Shea JA. Assessing the relationship between housing and health among medically complex, chronically homeless individuals experiencing frequent hospital use in the United States. Health & Social Care in the Community. 2020;28(1):91–99.31476092
25 Child J, Bierer M, Eagle K. Unexpected factors predict control of hypertension in a hospital-based homeless clinic. Mt Sinai J Med. 1998;65(4):304–307.9757754
26 Christensen RC, Cournos F. Community psychiatry education through homeless outreach. Psychiatr Serv. 2004;55(8):942.
27 Chrystal JG, Glover DL, Young AS, . Experience of primary care among homeless individuals with mental health conditions. PLoS ONE [Electronic Resource]. 2015;10(2):e0117395.
28 Ciaranello AL, Molitor F, Leamon M, . Providing health care services to the formerly homeless: a quasi-experimental evaluation. J Health Care Poor Underserved. 2006;17(2):441–461.16702726
29 Clark C, Rich AR. Outcomes of homeless adults with mental illness in a housing program and in case management only. Psychiatr Serv. 2003;54(1):78–83.12509671
30 Clark C, Teague GB, Henry RM. Preventing homelessness in Florida. Alcoholism Treatment Quarterly. 1999;17(1–2):73–91.
31 Integrating training and research with clinical services in a community setting. Hosp Community Psychiatry. 1989;40(11):1175–1179.2807226
32 Conovkr S, Berkman A, Gheith A, . Methods for successful follow-up of elusive urban populations: An ethnographic approach with homeless men. Bulletin of the New York Academy of Medicine: Journal of Urban Health. 1997;74(1):90–108.9211004
33 Culhane D, Metraux S, Hadley T. Public service reductions associated with placement of homeless persons with severe mental illness in supportive housing. Housing Policy Debate. 2002(13):107–163.
34 Currie LB, Patterson ML, Moniruzzaman A, McCandless LC, Somers JM. Continuity of Care among People Experiencing Homelessness and Mental Illness: Does Community Follow-up Reduce Rehospitalization? Health Serv Res. 2018;53(5):3400–3415.29896793
35 Darbyshire P, Muir-Cochrane E, Fereday J, Jureidini J, Drummond A. Engagement with health and social care services: perceptions of homeless young people with mental health problems. Health & Social Care in the Community. 2006;14(6):553–562.17059497
36 Dates B, Young MS, Bennett-Clark F, . Assertive community treatment fidelity in programs serving persons who are homeless with co-occurring mental and addictive disorders. J Dual Diagn. 2009;5(3–4):264–286.
37 Davis C. Health care for homeless people: the role of emergency nurses. Emerg Nurse. 2012;20(2):24–27; quiz 29.
38 Deas-Nesmith D, McLeod-Bryant S. Psychiatric deinstitutionalization and its cultural insensitivity: consequences and recommendations for the future. J Natl Med Assoc. 1992;84(12):1036–1040.1296996
39 Dennis DL, Steadman HJ, Cocozza JJ. The impact of federal systems integration initiatives on services for mentally ill homeless persons. Mental Health Services Research. 2000;2(3):165–174.11256725
40 Desai MM, Rosenheck RA. Unmet need for medical care among homeless adults with serious mental illness. Gen Hosp Psychiatry. 2005;27(6):418–425.16271656
41 Dickey B. Review of programs for persons who are homeless and mentally ill. Harv Rev Psychiatry. 2000;8(5):242–250.11118233
42 Dickins K, Buchholz SW, Ingram D, . “Now that you’ve got that coverage”: Promoting use of a regular source of primary care among homeless persons. J Am Assoc Nurse Pract. 2019;13:13.
43 Doering TJ, Hermes E, Konitzer M, Fischer GC, Steuernagel B. [Health situation of homeless in a health care home in Hannover]. Gesundheitswesen. 2002;64(6):375–382.12063650
44 Dorney-Smith S. Nurse-led homeless intermediate care: an economic evaluation. Br J Nurs. 2011;20(18):1193–1197.22067642
45 Douglass KM, Polcari A, Najjar N, Kronenfeld J, Deshpande AR. Health Care for the Homeless Transgender Community: Psychiatric Services and Transition Care at a Student-Run Clinic. J Health Care Poor Underserved. 2018;29(3):940–948.30122674
46 Elissen AM, Van Raak AJ, Derckx EW, Vrijhoef HJ. Improving homeless persons’ utilisation of primary care: Lessons to be learned from an outreach programme in The Netherlands. International Journal of Social Welfare. 2013;22(1):80–89.
47 Ellison ML, Schutt RK, Glickman ME, . Patterns and predictors of engagement in peer support among homeless veterans with mental health conditions and substance use histories. Psychiatric Rehabilitation Journal. 2016;39(3):266–273.27618463
48 Essendorfer L. [Structures of professional nursing in the care of homeless persons: orienting to living conditions]. Pflege Z. 2007;60(12):666–669.18200982
49 Fernandez J. On planning a service for the homeless mentally ill in Dublin. International Journal of Family Psychiatry. 1985;6(2):149–163.
50 Ferreira CP, Rozendo CA, Melo GB. [A Street Clinic in a state capital in Northeast Brazil from the perspective of homeless people]. Cad Saude Publica. 2016;32(8):e00070515.27509548
51 Flores EJ. The Honolulu VA Hoptel: an option for the mentally ill homeless veteran. Continuum (Chicago). 1998;18(6):13–17.
52 Fournier AM, Perez-Stable A, Greer PJ, Jr. Lessons from a clinic for the homeless. The Camillus Health Concern. JAMA. 1993;270(22):2721–2724.8133591
53 Fraino JA. Mobile Nurse Practitioner: A Pilot Program to Address Service Gaps Experienced by Homeless Individuals. J Psychosoc Nurs Ment Health Serv. 2015;53(7):38–43.
54 Gabrielian S, Chen JC, Minhaj BP, . Feasibility and Acceptability of a Colocated Homeless-Tailored Primary Care Clinic and Emergency Department. J Prim Care Community Health. 2017;8(4):338–344.28367682
55 Gabrielian S, Yuan AH, Andersen RM, Gelberg L. Diagnoses Treated in Ambulatory Care Among Homeless-Experienced Veterans: Does Supported Housing Matter? J Prim Care Community Health. 2016;7(4):281–287.27343544
56 Gabrielian S, Yuan AH, Andersen RM, Rubenstein LV, Gelberg L. VA health service utilization for homeless and low-income Veterans: a spotlight on the VA Supportive Housing (VASH) program in greater Los Angeles. Med Care. 2014;52(5):454–461.24714583
57 Gatewood SB, Moczygemba LR, Alexander AJ, . Development and Implementation of an Academic-Community Partnership to Enhance Care among Homeless Persons. Inov Pharm. 2011;2(1):1–7.22259752
58 Gelberg L, Doblin BH, Leake BD. Ambulatory health services provided to low-income and homeless adult patients in a major community health center. J Gen Intern Med. 1996;11(3):156–162.8667092
59 Gordon AJ, Montlack ML, Freyder P, . The Allegheny initiative for mental health integration for the homeless: integrating heterogeneous health services for homeless persons. Am J Public Health. 2007;97(3):401–405.17267708
60 Gundlapalli AV, Redd A, Bolton D, . Patient-aligned Care Team Engagement to Connect Veterans Experiencing Homelessness With Appropriate Health Care. Med Care. 2017;55 Suppl 9 Suppl 2:S104–S110.28806373
61 Gundlapalli A, Hanks M, Stevens SM, . It takes a village: a multidisciplinary model for the acute illness aftercare of individuals experiencing homelessness. J Health Care Poor Underserved. 2005;16(2):257–272.15937390
62 Gunner E, Chandan SK, Marwick S, . Provision and accessibility of primary healthcare services for people who are homeless: a qualitative study of patient perspectives in the UK. Br J Gen Pract. 2019;69(685):e526–e536.31307999
63 Hatton DC. Homeless women’s access to health services: a study of social networks and managed care in the US. Women Health. 2001;33(3–4):149–162.11527102
64 Henwood BF, Shinn M, Tsemberis S, Padgett DK. Examining provider perspectives within housing first and traditional programs. American Journal of Psychiatric Rehabilitation. 2013;16(4):262–274.24659925
65 Henwood BF, Weinstein LC, Tsemberis S. Creating a medical home for homeless persons with serious mental illness. Psychiatr Serv. 2011;62(5):561–562.21532088
66 Hoist H, Walsh C. A reflection on Victoria’s Statewide Homelessness Assessment and Referral Framework as a quality improvement initiative. Australian Journal of Primary Health. 2008;14(2):64–67.
67 Howe EC, Buck DS, Withers J. Delivering health care on the streets: challenges and opportunities for quality management. Qual Manag Health Care. 2009;18(4):239–246.19851231
68 Jego M, Abcaya J, Stefan DE, Calvet-Montredon C, Gentile S. Improving Health Care Management in Primary Care for Homeless People: A Literature Review. International Journal of Environmental Research & Public Health [Electronic Resource]. 2018;15(2):10.
69 Jego M, Grassineau D, Balique H, . Improving access and continuity of care for homeless people: how could general practitioners effectively contribute? Results from a mixed study. BMJ Open. 2016;6(11):e013610.
70 Johnson EE, Borgia M, Rose J, O’Toole TP. No wrong door: Can clinical care facilitate veteran engagement in housing services? Psychol Serv. 2017;14(2):167–173.28481601
71 Jones AL, Hausmann LRM, Haas GL, . A national evaluation of homeless and nonhomeless veterans’ experiences with primary care. Psychol Serv. 2017;14(2):174–183.28481602
72 Jones AL, Thomas R, Hedayati DO, Saba SK, Conley J, Gordon AJ. Patient predictors and utilization of health services within a medical home for homeless persons. Substance Abuse. 2018;39(3):354–360.29412071
73 Kaduszkiewicz H, Bochon B, van den Bussche H, Hansmann-Wiest J, van der Leeden C. The Medical Treatment of Homeless People. Deutsches Arzteblatt International. 2017;114(40):673–679.29070427
74 Kalton A, Falconer E, Docherty J, Alevras D, Brann D, Johnson K. Multi-Agent-Based Simulation of a Complex Ecosystem of Mental Health Care. J Med Syst. 2016;40(2):1–8.26573639
75 Kaplan-Weisman L, Sansone S, Walter E, Crump C. Feasibility of Advance Care Planning in Primary Care for Homeless Adults. J Aging Health. 2019:898264319862420.
76 Keogh C, O’Brien KK, Hoban A, O’Carroll A, Fahey T. Health and use of health services of people who are homeless and at risk of homelessness who receive free primary health care in Dublin. BMC Health Serv Res. 2015;15:58.25884629
77 Kerman N, Sylvestre J, Polillo A. The study of service use among homeless persons with mental illness: a methodological review. Health Services and Outcomes Research Methodology. 2016;16(1–2):41–57.
78 Kertesz SG, Holt CL, Steward JL, . Comparing homeless persons’ care experiences in tailored versus nontailored primary care programs. Am J Public Health. 2013;103 Suppl 2:S331–339.24148052
79 Kertesz SG, Posner MA, O’Connell JJ, . Post-hospital medical respite care and hospital readmission of homeless persons. Journal of Prevention & Intervention in the Community. 2009;37(2):129–142.19363773
80 Kessell ER, Bhatia R, Bamberger JD, Kushel MB. Public health care utilization in a cohort of homeless adult applicants to a supportive housing program. J Urban Health. 2006;83(5):860–873.16779686
81 Kirkland-Kyhn H. The nurse practitioner role in treating the homeless and rough-sleeper population. J Am Assoc Nurse Pract. 2020;32(4):287–289.32251210
82 Koh HK, O’Connell JJ. Improving Health Care for Homeless People. JAMA. 2016;316(24):2586–2587.28027356
83 Koon AD, Kantayya VS, Choucair B. Homelessness and health care: considerations for evaluation, management, and support within the primary care domain. Dis Mon. 2010;56(12):719–733.21168578
84 Kuehn BM. Hospitals Turn to Housing to Help Homeless Patients. JAMA. 2019;321(9):822–824.30758505
85 Lam JA, Rosenheck R. Social support and service use among homeless persons with serious mental illness. Int J Soc Psychiatry. 1999;45(1):13–28.10443246
86 Lamanna D, Stergiopoulos V, Durbin J, O’Campo P, Poremski D, Tepper J. Promoting continuity of care for homeless adults with unmet health needs: The role of brief interventions. Health & Social Care in the Community. 2018;26(1):56–64.28569397
87 Lashley M. An on-site health home for homeless men in addiction recovery. Public Health Nurs. 2019;36(2):184–191.30536667
88 Lee SJ, Crowther E, Keating C, Kulkarni J. What is needed to deliver collaborative care to address comorbidity more effectively for adults with a severe mental illness? Aust N Z J Psychiatry. 2013;47(4):333–346.23076548
89 Levy BD, O’Connell JJ. Health care for homeless persons. N Engl J Med. 2004;350(23):2329–2332.15175433
90 Liu CY, Chai SJ, Watt JP. Communicable disease among people experiencing homelessness in California. Epidemiol Infect. 2020;148:e85.32223777
91 Luchenski S, Maguire N, Aldridge RW, . What works in inclusion health: overview of effective interventions for marginalised and excluded populations. Lancet. 2018;391(10117):266–280.29137868
92 Madrid PA, Sinclair H, Bankston AQ, . Building integrated mental health and medical programs for vulnerable populations post-disaster: connecting children and families to a medical home. Prehosp Disaster Med. 2008;23(4):314–321.18935945
93 Marshall M, Lockwood A, Gath D. Social services case-management for long-term mental disorders: a randomised controlled trial. Lancet. 1995;345(8947):409–412.7853949
94 McGuire J. Closing a front door to homelessness among veterans. J Prim Prev. 2007;28(3–4):389–400.17549637
95 McGuire JF, Rosenheck RA. Criminal History as a Prognostic Indicator in the Treatment of Homeless People with Severe Mental Illness. Psychiatr Serv. 2004;55(1):42–48.14699199
96 McGuire J, Rosenheck R, Burnette C. Expanding service delivery: does it improve relationships among agencies serving homeless people with mental illness? Adm Policy Ment Health. 2002;29(3):243–256.12033669
97 McInnes DK, Petrakis BA, Gifford AL, . Retaining homeless veterans in outpatient care: a pilot study of mobile phone text message appointment reminders. Am J Public Health. 2014;104 Suppl 4:S588–594.25100425
98 Mehta P, Brown A, Chung B, . Community partners in care: 6-month outcomes of two quality improvement depression care interventions in male participants. Ethn Dis. 2017;27(3):223–232.28811733
99 Mercuel A. [Homelessness: psychological and behavioral issues]. Bulletin de l Academie Nationale de Medecine. 2013;197(2):271–276.24919358
100 Mishan LI, Dragatsi D. Student-Run Clinics: A Novel Approach to Integrated Care, Teaching and Recruitment. Community Ment Health J. 2017;53(4):460–463.28194598
101 Montgomery P, Forchuk C, Duncan C, Rose D, Bailey PH, Veluri R. Supported housing programs for persons with serious mental illness in rural northern communities: a mixed method evaluation. BMC Health Serv Res. 2008;8:156.18652689
102 Moore DT, Rosenheck RA. Comprehensive services delivery and emergency department use among chronically homeless adults. Psychol Serv. 2017;14(2):184–192.28481603
103 Moore M, Conrick KM, Reddy A, Allen A, Jaffe C. From Their Perspective: The Connection between Life Stressors and Health Care Service Use Patterns of Homeless Frequent Users of the Emergency Department. Health Soc Work. 2019;44(2):113–122.30855682
104 Morrissey JP, Calloway MO, Thakur N, . Integration of service systems for homeless persons with serious mental illness through the ACCESS program. Access to Community Care and Effective Services and Supports. Psychiatr Serv. 2002;53(8):949–957.12161668
105 Morse GA, Calsyn RJ, Klinkenberg WD, . An experimental comparison of three types of case management for homeless mentally ill persons. Psychiatr Serv. 1997;48(4):497–503.9090733
106 Mowbray CT, Cohen E, Harris S, Trosch S, Johnson S, Duncan B. Serving the homeless mentally ill: Mental health linkage. J Community Psychol. 1992;20(3):215–227.
107 Myers R. Fully-integrated medical home for people with severe and persistent mental illness: A description and outcome analysis of a medicare advantage chronic special needs program. Mental Illness. 2018;10(2):48–52.
108 Nakashima J, McGuire J, Berman S, Daniels W. Developing programs for homeless veterans: understanding driving forces in implementation. Soc Work Health Care. 2004;40(2):1–12.
109 Nakonezny PA, Ojeda M. Health services utilization between older and younger homeless adults. Gerontologist. 2005;45(2):249–254.15799990
110 Ng AT, McQuistion HL. Outreach to the Homeless: Craft, Science, and Future Implications. J Psychiatr Pract. 2004;10(2):95–105.15330405
111 No authorship i. Gold award: A network of services for the homeless chronic mentally ill: Skid Row Mental Health Service, Los Angeles County Department of Mental Health. Hosp Community Psychiatry. 1986;37(11):1148–1151.3781505
112 O’Toole TP, Bourgault C, Johnson EE, . New to care: demands on a health system when homeless veterans are enrolled in a medical home model. Am J Public Health. 2013;103 Suppl 2:S374–379.24148042
113 O’Toole TP, Buckel L, Bourgault C, . Applying the chronic care model to homeless veterans: effect of a population approach to primary care on utilization and clinical outcomes. Am J Public Health. 2010;100(12):2493–2499.20966377
114 O’Toole TP, Johnson EE, Aiello R, Kane V, Pape L. Tailoring Care to Vulnerable Populations by Incorporating Social Determinants of Health: the Veterans Health Administration’s “Homeless Patient Aligned Care Team” Program. Prev Chronic Dis. 2016;13:E44.27032987
115 O’Toole TP, Johnson EE, Borgia ML, Rose J. Tailoring Outreach Efforts to Increase Primary Care Use Among Homeless Veterans: Results of a Randomized Controlled Trial. J Gen Intern Med. 2015;30(7):886–898.25673574
116 O’Toole TP, Johnson EE, Borgia M, . Population-Tailored Care for Homeless Veterans and Acute Care Use, Cost, and Satisfaction: A Prospective Quasi-Experimental Trial. Prev Chronic Dis. 2018;15:E23.29451116
117 O’Toole TP, Pirraglia PA, Dosa D, . Building care systems to improve access for high-risk and vulnerable veteran populations. J Gen Intern Med. 2011;26 Suppl 2:683–688.
118 Parker S, Dark F, Newman E, Hanley D, McKinlay W, Meurk C. Consumers’ understanding and expectations of a community-based recovery-oriented mental health rehabilitation unit: A pragmatic grounded theory analysis. Epidemiology and Psychiatric Sciences. 2019;28(4):408–417.29199920
119 Paudyal V, Saunders K. Homeless reduction act in England: impact on health services. Lancet. 2018;392(10143):195–197.30043743
120 Pauly JB, Moore TA, Shishko I. Integrating a mental health clinical pharmacy specialist into the Homeless Patient Aligned Care Teams. The Mental Health Clinician. 2018;8(4):169–174.30155391
121 Pfeil M, Howe A. Ensuring primary care reaches the ‘hard to reach’. Qual Prim Care. 2004;12(3):185–190.
122 Pickett SA, Luther S, Stellon E, Batia K. Making integrated care a reality: Lessons learned from Heartland Health Outreach’s integration implementation. American Journal of Psychiatric Rehabilitation. 2015;18(1):87–104.
123 Podymow T, Turnbull J, Tadic V, Muckle W. Shelter-based convalescence for homeless adults. Can J Public Health. 2006;97(5):379–383.17120876
124 Pollio DE, Spitznagel EL, North CS, Thompson S, Foster DA. Service use over time and achievement of stable housing in a mentally ill homeless population. Psychiatr Serv. 2000;51(12):1536–1543.11097650
125 Purkey E, MacKenzie M. Experience of healthcare among the homeless and vulnerably housed a qualitative study: opportunities for equity-oriented health care. International Journal for Equity in Health. 2019;18(1):101.31262310
126 Putnam JF, Cohen NL, Sullivan AM. Innovative outreach services for the homeless mentally ill. Int J Ment Health. 1985;14(4):4+112–124.
127 Raines A, O’Connor T. City Health Conference: Improving Access to Primary Care Among the Homeless Population of Southall. Br J Gen Pract. 2019;69(685):394.
128 Resnik L, Ekerholm S, Johnson EE, Ellison ML, O’Toole TP. Which Homeless Veterans Benefit From a Peer Mentor and How? J Clin Psychol. 2017;73(9):1027–1047.27764527
129 Rogers MM, Schwartz J. Healthcare for the homeless. A public health agency, a business, and a Catholic provider open a clinic. Health Prog. 1993;74(10):58–60.
130 Rosenbaum N, Tinney DM, Tohen M. Collaboration to reduce tragedy and improve outcomes: Law enforcement, psychiatry, and people living with mental illness. Am J Psychiatry. 2017;174(6):513–517.28565948
131 Rosenheck R, Frisman L, Gallup P. Effectiveness and cost of specific treatment elements in a program for homeless mentally ill veterans. Psychiatr Serv. 1995;46(11):1131–1139.8564501
132 Rosenheck R, Lam JA. Client and site characteristics as barriers to service use by homeless persons with serious mental illness. Psychiatr Serv. 1997;48(3):387–390.9057243
133 Rosenheck R, Morrissey J, Lam J, . Service system integration, access to services, and housing outcomes in a program for homeless persons with severe mental illness. Am J Public Health. 1998;88(11):1610–1615.9807525
134 Rothbard AB, Min SY, Kuno E, Wong YL. Long-term effectiveness of the ACCESS program in linking community mental health services to homeless persons with serious mental illness. J Behav Health Serv Res. 2004;31(4):441–449.15602144
135 Rowe M, Styron T, David DH. Mental Health Outreach to Persons Who are Homeless: Implications for Practice from a Statewide Study. Community Ment Health J. 2016;52(1):56–65.26711095
136 Salize HJ, Werner A, Jacke CO. Service provision for mentally disordered homeless people. Current Opinion in Psychiatry. 2013;26(4):355–361.23695530
137 Sarango M, de Groot A, Hirschi M, Umeh CA, Rajabiun S. The Role of Patient Navigators in Building a Medical Home for Multiply Diagnosed HIV-Positive Homeless Populations. J Public Health Manag Pract. 2017;23(3):276–282.28079645
138 Sestito SF, Rodriguez KL, Saba SK, Conley JW, Mitchell MA, Gordon AJ. Homeless veterans’ experiences with substance use, recovery, and treatment through photo elicitation. Substance Abuse. 2017;38(4):422–431.28726549
139 Shepherd M, Gunnell D, Maxwell B, Mumford D. Development and evaluation of an inner city mental health team. Soc Psychiatry Psychiatr Epidemiol. 1998;33(3):129–135.9540388
140 Shortt SE, Hwang S, Stuart H, Bedore M, Zurba N, Darling M. Delivering primary care to homeless persons: a policy analysis approach to evaluating the options. Healthcare Policy = Politiques de sante. 2008;4(1):108–122.19377346
141 Simmons MM, Gabrielian S, Byrne T, . A Hybrid III stepped wedge cluster randomized trial testing an implementation strategy to facilitate the use of an evidence-based practice in VA Homeless Primary Care Treatment Programs. Implementation Science. 2017;12(1):46.28376839
142 Smelson DA, Chinman M, Hannah G, Byrne T, McCarthy S. An evidence-based co-occurring disorder intervention in VA homeless programs: outcomes from a hybrid III trial. BMC Health Serv Res. 2018;18(1):332.29728148
143 Snyder MD, Weyer ME. Facilitating a collaborative partnership with a homeless shelter. J Nurs Educ. 2002;41(12):547–549.12530570
144 Stein JA, Andersen RM, Koegel P, Gelberg L. Predicting health services utilization among homeless adults: a prospective analysis. J Health Care Poor Underserved. 2000;11(2):212–230.10793516
145 Stergiopoulos V, Hwang S, Gozdzik A, . At Home/Chez soi Investigators. Effect of scattered-site housing using rent supplements and intensive case management on housing stability among homeless adults with mental illness: a randomized trial. JAMA - Journal of the American Medical Association. 2015:905–915.25734732
146 Strange C, Fisher C, Arnold-Reed D, Brett T, Ping-Delfos WCS. A general practice street health service: Patient and allied service provider perspectives. Australian Journal Of General Practice. 2018;47(1–2):44–49.29429315
147 Sumalinog R, Harrington K, Dosani N, Hwang SW. Advance care planning, palliative care, and end-of-life care interventions for homeless people: A systematic review. Palliat Med. 2017;31(2):109–119.27260169
148 Summerside K. Making it matter: improving the health of young homeless people. Mental Health Today. 2013:18–19.
149 Swabri J, Uzor C, Laird E, O’Carroll A. Health status of the homeless in Dublin: does the mobile health clinic improve access to primary healthcare for its users? Ir J Med Sci. 2019;188(2):545–554.30178074
150 Timms P, Perry J. Sectioning on the street - futility or utility? Bjpsych Bulletin. 2016;40(6):302–305.28377807
151 Tollett JH, Thomas SP. A theory-based nursing intervention to instill hope in homeless veterans. Advances in Nursing Science. 1995;18(2):76–90.8585710
152 Trabert G. [Medical Care for Homeless People - Individual Right and a Social Duty for an Inclusive Society]. Gesundheitswesen. 2016;78(2):107–112.26906536
153 Tsai J, Gelberg L, Rosenheck RA. Changes in Physical Health After Supported Housing: Results from the Collaborative Initiative to End Chronic Homelessness. J Gen Intern Med. 2019;34(9):1703–1708.31161570
154 Tyner AP. Happenings spotlight: student nurses step into action to support local VA initiative serving homeless veterans. Imprint. 2014;61(3):23–24.
155 Upshur CC, Jenkins D, Weinreb L, Gelberg L, Orvek EA. Prevalence and predictors of substance use disorders among homeless women seeking primary care: An 11 site survey. Am J Addict. 2017;26(7):680–688.28677919
156 Vargas ER, Macerata I. [Contributions of Street Outreach teams to primary health care and managementContribuciones de los equipos de Consultorio en la Calle para el cuidado y la gestion de la atencion basica]. Pan American Journal of Public Health. 2018;42:e170.31093198
157 Vazquez Souza MI. The mental health unit for the homeless mentally ill. Estudos de Psicologia. 2011;16(3):353–362.
158 Vickery KD, Shippee ND, Menk J, . Integrated, Accountable Care For Medicaid Expansion Enrollees: A Comparative Evaluation of Hennepin Health. Med Care Res Rev. 2020;77(1):46–59.29749302
159 Weinreb L, Nicholson J, Williams V, Anthes F. Integrating behavioral health services for homeless mothers and children in primary care. Am J Orthopsychiatry. 2007;77(1):142–152.17352595
160 Wenger LD, Leadbetter J, Guzman L, Kral A. The making of a resource center for homeless people in San Francisco’s Mission District: a community collaboration. Health Soc Work. 2007;32(4):309–314.18038733
161 Wijk LBV, Mangia EF. [Psychosocial care and healthcare for the homeless population: an integrative review]. Ciencia & Saude Coletiva. 2019;24(9):3357–3368.31508756
162 Wilkins C. Connecting permanent supportive housing to health care delivery and payment systems: Opportunities and challenges. American Journal of Psychiatric Rehabilitation. 2015;18(1):65–86.
163 Worley NK, Drago L, Hadley T. Improving the physical health-mental health interface for the chronically mentally ill: Could nurse case managers make a difference? Arch Psychiatr Nurs. 1990;4(2):108–113.2357108
164 Wright BJ, Vartanian KB, Li HF, Royal N, Matson JK. Formerly Homeless People Had Lower Overall Health Care Expenditures After Moving Into Supportive Housing. Health Aff (Millwood). 2016;35(1):20–27.26733697
165 Wright NM, Tompkins CN, Oldham NS, Kay DJ. Homelessness and health: what can be done in general practice? J R Soc Med. 2004;97(4):170–173.15056737
166 Zerger S, Doblin B, Thompson L. Medical respite care for homeless people: a growing national phenomenon. J Health Care Poor Underserved. 2009;20(1):36–41.
167 Zlotnick C, Zerger S, Wolfe PB. Health care for the homeless: what we have learned in the past 30 years and what’s next. Am J Public Health. 2013;103 Suppl 2:S199–205.24148056