# APPENDIX E REPORTED FINDINGS BY INCLUDED STUDY

Study | Study Design Number of Patients Length of Follow Up | Number of Intervention Strategies | Primary Care Integration Approach Core Disciplines | Relevant Author-Reported Key Findings
Baker, 2018^32^ | - Program evaluation; - n=212; - Subgroup of patients followed for 6+ months | Patient: 6; Clinic: 2; System: 1 | - Enhanced referral Psychiatry,; - psychiatric/mental health nurse practitioners | Main finding from abstract: “All clients were housed and none incarcerated. From 2008 to 2010, only 3% of clients were hospitalized, compared to 7.5% of adults with SMI [population estimate].”
Corrigan, 2017^33^ | - Randomized controlled trial; - n=67; - 12 months | Patient: 4; Clinic: 2; System: 0 | - Standard referral; - Peer support | Main finding from abstract: “Findings from group by trial ANOVAs of omnibus measures of the four constructs [physical and mental health, recovery, and quality of life] showed significant impact over the one year for participants in PNP compared to control described by small to moderate effect sizes. These differences emerged even though both groups showed significant improvements in reduced homelessness and insurance coverage.”
Kelly, 2018^31^ | - Randomized controlled trial; - study; - n=20; - 6 months | Patient: 6; Clinic: 3; System: 2 | - Standard referral; - Peer health navigator, psychiatry, behavioral health, case management, housing support | Main finding from abstract: “Health navigator contacts and use of personal health records were associated with improvements in health care and self-management.”
McGuire 2009^37^ | - Single site controlled before-after study; - n=260; - 18 months | Patient: 6; Clinic: 1; System: 0 | - Co-located, interdisciplinary care planning; - Case manager, behavioral health, psychiatrist, nursing, primary care, housing services | Main finding from abstract: “… the integrated care group was more rapidly enrolled in primary care, received more prevention services and primary care visits, and fewer emergency department visits, and was not different in inpatient utilization or in physical health status …The demonstration clinic improved access to primary care services and reduced emergency services but did not improve perceived physical health status.”
Patterson, 2012^47^ | - Cohort; - n=536; - At least 6 months | Patient: 2; Clinic: 0; System: 1 | - Co-located, enhanced referral; - Behavioral health, psychiatrist, nursing, primary care | Main finding from abstract: Pre-post enrollment period comparisons “indicated significant improvements in health and social service involvement and reductions in offending.”
Rivas-Vazquez, 2009^36^ | - Cohort; - n=229; - Not reported | Patient: 9; Clinic: 2; System: 0 | - Co-located, interdisciplinary care planning; - Case manager, behavioral health provider, primary care | Main finding from abstract: “A highly significant reduction in arrest rates for individuals diverted to the relationship-based care program was observed. However, the arrest rate for the control group remained nearly identical before and after diversion. For the relationship-based care group, pre-diversion arrest rates, duration of participation in the program, and number of psychiatric contacts accounted for a significant portion of the recidivism variance.”
Rosenheck, 1993^45^ | - Cohort; - n=1748; - 12 months | Patient: 2; Clinic: 0; System: 0 | - Enhanced referral; - Behavioral health, nursing | Main finding from abstract: “Although utilization of inpatient services did not increase after veterans’ initial contact with the program, use of domiciliary and outpatient services increased substantially. Total annual costs to the VA also increased by 35%…. Both clinical need and participation in the program were associated with increased use of health services and increased cost.”
Stanhope, 2014^30^ | - Qualitative study; - n=15; - Not applicable | Patient: 4; Clinic: 1; System: 0 | - Integrative care planning; - Primary care | All thematic findings as reported by authors; [underlined: Consumer identified barriers to addressing health needs:]; Internal Barriers:; - “Postponement: Being in denial about their health was driven both by a minimization of their symptoms and a fear of what they might find if they sought care.” (p 659); - “Depends on my mood: The role that mental health symptoms played in people’s ability to reach out for help and take steps to improve their health was profound.” (p 659); External Barriers:; - “Now that I have a place to stay. I can start dealing with me: Participants described addressing their health needs in the context of transitioning to housing”; - “The system: Many participants expressed a deep distrust of the health care system which emerged both from direct experiences of discrimination due to their mental health problems and being homeless and also a general skepticism surrounding an insurance based system.” (p 660); [underlined: Overcoming Barriers]:; - “Getting out of our own heads: The most significant part of the self-management group was the peer support process that emerged from their weekly sessions.” (p 661); - “Trusting my own voice: With increased knowledge and encouragement from the group, the participants felt more able to take control of their health, which often meant grappling with the internal and external barriers they had encountered.”
Solomon, 1988^48^ | - Program evaluation; - Not applicable; - Not applicable | Patient: 2; Clinic: 2; System: 0 | - Enhanced referral; - Behavioral health, psychiatry, nursing, primary care, case manager | Conclusion as reported by author: “A mental health project such as this needs to be flexible in its efforts to serve homeless persons who are generally suspicious of others and resistant to using traditional mental health services. Thought needs to be given to developing a non-stigmatizing identity for such a program.” (p 13)
Stergiopoulos, 2012^49^ Stergiopoulos, 2017^62^ | - Qualitative program evaluation; - n=204; - Not applicable | Patient: 8; Clinic: 1; System: 0 | - Standard referral; - Psychiatry, case manager | Main finding from abstract: “The target population had complex health and social needs. The [intervention] enjoyed a high degree of fidelity…. Program providers reported congruence of these philosophies of practice, and program participants valued the program and its components.”
Stergiopoulos, 2018^28^ | - Cohort study; - n=391; - 6 months | Patient: 5; Clinic: 1; System: 0 | - Co-located, enhanced referral; - Not reported | Main finding from abstract: “Participants had statistically significant improvements in mental and physical health status and reductions in mental health symptoms, substance misuse and the number of hospital admissions. Strength of working alliance…. associated with reduced health care use and mental health symptoms.”
Stergiopoulos, 2015^34^ | - Controlled before-after study; - n=140; - 12 months | [underlined: Agency A]; Patient: 4; Clinic: 1; System: 1; [underlined: Agency B] Patient: 4; Clinic: 1; System: 1 | [underlined: Agency A (Integrated] [underlined: multidisciplinary collaborative] [underlined: care model)]; - Co-located, interdisciplinary care planning; - Psychiatry, primary care, case manager, shelter staff; [underlined: Agency B (shifted outpatient collaborative care model)]; - Standard referral; - Psychiatry, case manager, shelter staff | Main finding from abstract: “We observed improvements in both programs over time on measures of community functioning, residential stability, hospitalizations, emergency department visits and community physician visits, with no significant differences between groups over time”
Weinstein, 2013^35^ | - Program evaluation; - n=Not reported; - Not reported | Patient: 6; Clinic: 2; System: 1 | - Co-located, enhanced referral; - Licensed clinical social worker, psychiatrist, nursing, primary care, peer specialist | Main finding from abstract: “Preliminary program evaluation results suggest that this partnership is evolving to function as an integrated personcentered health home and an effective local public health monitoring system”
Weinstein, 2013^46^ | - Cross-sectional; - n=123; - Not reported | Patient: 4; Clinic: 0; System: 2 | - Co-location, interdisciplinary care planning, enhanced referral,; - Psychiatrist, nursing, primary care | Main finding from abstract: “Participants had high rates of comorbid chronic disease and risk behavior…The integrated care program subgroup had relatively high rates of documentation of some health care quality indicators: 62% with BMI, 73% with BP, 77% with tobacco use history, 87% with substance use history.”
ACCESS: Multi-site federal demonstration project; nonrandomized cohort; strategies employed and approaches to primary care integration varied across sites
Calloway, 1998^42^ | Main finding from abstract: “In 1994 and 1996, of the 20,801 pairs of potential service linkages, about a third were in place while the remaining two-thirds were absent. Overall, linkages showed a slight but significant increase between 1994 and 1996. More than half of the linkages changed in type, indicating a fluid service system”
Cheng, 2008^38^ | Main finding from abstract “After 18 months of follow up, women had significantly better outcomes in terms of family relationships (est. mean score increased 0.100), victimization (score decreased 0.164), and social support (score increased 0.363) than did men (all, p<0001). Being accompanied by children was significantly associated with less change in drug use among women compared to men (p<0.01)”
Cocozza, 2000^41^ | Lessons suggested by data as reported by authors: “It is possible to systematically monitor and measure the strategies used by localities in their efforts to better integrate service delivery systems.” “Some strategies have a higher probability of successful implementation than others.” “There are patterns in the selection of system integration strategies across sites” “when supported, communities can develop and implement a variety of strategies for integrating services” (p 405-406)
Morrissey, 1997^44^ | Main finding from abstract “Services at baseline for homeless mentally ill persons at the program sites were rates as relatively inaccessible, and the coordination of services between agencies was rates as even more problematic…. On average, at baseline agencies that had received an ACCESS grant were better connected to their local service network than were other agencies”
Rosenheck, 1997^43^ | Main finding from abstract: “The greatest differences between clients’ and providers perceptions of service needs were in dental and medical services, which were more frequently identified as needs by clients, and in substance abuse and mental health services which were more frequently identified by providers. Clients’ and providers assessments of need were significantly, but not strongly, correlated with each other, and both were correlated with use of MH and substance use services””
Rosenheck, 2002^40^ | Main finding from abstract: “…clients at the experimental sites showed no greater improvement on measures of MH or housing…across four cohorts than those at the comparison sites. More extensive implementation of system integration strategies was unrelated to these outcomes…clients of sites that became more integrated…had progressively better housing outcomes.”
Steadman, 2002^39^ | Conclusion as reported by author: “Fully 17 or the 18 ACCESS sites were continuing to provide services to homeless persons with SMI and co-occurring substance abuse by using parts or all of the ACCESS model” (p 491)