# APPENDIX D SUMMARY OF OUTCOME MEASURES

General Outcome Measure | Specific Outcome Measure | Follow-up Range | Study
Patient Level
Mental and physical health
Mental health, general^a^ | SF 36; Diagnostic Interview Schedule; Psychiatric; Epidemiology Research Interview; Psychiatric Problem; Index; TCU Health Form; Recovery assessment Scale;; Colorado Symptom Index, modified; Brief Psychiatric Rating Scale | Baseline to 18 months | ACCESS^40^; Non-ACCESS^28,33,34,37,45^
Substance use^a^ | Addiction Severity Index; self-report | Baseline to 18 months | ACCESS^38,40^; Non-ACCESS^28,34,37,45^
Physical health, general^a^ | SF-36 | Baseline to 18 months | Non-ACCESS^28,37^
Physical health, specific | Number of chronic conditions, specific conditions diagnosed | Not reported | Non-ACCESS^46^
Pain | SF-12 | Baseline to 6 months | Non-ACCESS^31^
Community functioning, community integration, and quality of life
Quality of life | Lehman QoLI-20; single summary question | Baseline to 12 months | ACCESS^40^; Non-ACCESS^28,33^
Victimization | Sum of items about frequency of physical victimization in last 2 months (Lehman quality of life) | Baseline to 18 months | ACCESS^38^
Criminal justice involvement | Number of incarcerations among “regularly followed clients”; post-diversion arrest rate; criminal justice status (parole or probation); number of offenses | 12 months to 2 years | Non-ACCESS^32,36,37,47^
Community functioning | Multnomah Community Ability Scale | Baseline to 12 months | Non-ACCESS^34^
Health care selfmanagement | Adapted Mental Health Confidence Scale | Baseline to 6 months | Non-ACCESS^31^
Housing | Residential Time Line Follow-Back Calendar; selfreported # days on street/in shelter; self-reported # of moves in past 12 months; self-reported lifetime duration of experiences of homelessness; achievement of independent housing domiciliary days | Baseline to 12 months | ACCESS^40^; Non-ACCESS^28,33,34,45^
Social support^a^ | Four unspecified questions about friends or professionals encouraging medical services in last 12 months;# people from 9 different categories (eg, parent, sibling, coworker, friend) with whom the subject felt close; National Vietnam Veterans’ Readjustment Study Scale | Baseline to 18 months | ACCESS^38^; Non-ACCESS^37^
Care utilization
Hospitalizations | Self-report; days psychiatric inpatient stay; days medical-surgical inpatient stay | Baseline to 12 months, “years” | Non-ACCESS^28,32,34,45,47^
Health and social service utilization^b^ | Health care and Health care utilization scale; “health and social service use” in last 60 days; Receipt of “public support payments and housing subsidies”; having a primary case manager | Baseline to 12 months | ACCESS^40^; Non-ACCESS^31^
Emergency department visit | Self-report; EHR based | 3 to 18 months | Non-ACCESS^28,34,37^
Primary care visits | Self-report # in last 30 days; EHR-based data collection | Baseline to 18 months | Non-ACCESS^34,37^
Psychiatric visits (outpatient) | Number per individual | 12 months | Non-ACCESS^37,45^
Outpatient visits (other) | Number of medical-surgical visits per individual; # healt-hrelated appointments (scheduled/achieved) | 12 months | Non-ACCESS^33,45^
Primary care access | Number of days to primary care visit following enrollment | Not applicable | Non-ACCESS^37^
Intervention engagement | Time spent in program (days); total # clinical contacts; attendance record service contact logs | 12 months | Non-ACCESS^36,48^
Receipt of financial support | Shelter payments; total social assistance | 12 months | Non-ACCESS^47^
Patient-level service integration | # of domains (ie, housing support, mental health, substance abuse, general health care, public income support, vocational rehab) in which services were received | Baseline to 12 months | ACCESS^40^
Health Care costs | Site-specific cost per service received; $ for outpatient medical services per individual per year | 6 to 12 months | Non-ACCESS^45,47^
Insurance coverage | Receipt insurance coverage | 12 months | Non-ACCESS^33^
Receipt of health screenings | Self-report; summary prevention services ratio based from EHR | Baseline to 12 months | Non-ACCESS^31,37^
Patient experience and quality of care
Quality of care | National Association of State Mental Health Program; Directors indicators; Healthcare Effectiveness Data Information Set | | Non-ACCESS^46^
Participant perspective on program | Participant perspectives on program model | | Non-ACCESS^49^
Patient-provider alliance | Working Alliance Inventory-Participant | 6 weeks to 6 months | Non-ACCESS^28,31^
PCP relationship | Engagement with the Health Care Provider Scale | Baseline to 6 months | Non-ACCESS^31^
Unmet needs or barriers to care
Competing needs | 5-item scale | | Non-ACCESS^37^
Barriers and facilitators to addressing health needs | Semi-structured interviews | Not applicable | Non-ACCESS^30^
Perceived need | Patient-perceived need, provider assessment of patient need and differences between the two | Baseline | ACCESS^43^
Clinic Level
Volume of care provided
Collaborative personal health record utilization | Count of log-ins | 6 months | Non-ACCESS^31^
Psychiatric evaluations by program | Visits attended | 2 years | Non-ACCESS^32^
Preventive services | Percentage of patient population receiving preventive services | Not reported | Non-ACCESS^35^
Quality of clinical care provided
Program performance | Local Public Health System Performance Assessment Instrument | Not applicable | Non-ACCESS^35^
Primary care medical home alignment | Overlap between intervention components and primary care medical home elements | Not applicable | Non-ACCESS^35^
Fidelity to care model | Measure of fidelity to assertive community treatment model; Fidelity evaluation via qualitative data collection (eg, observations, interviews) | 12 months to 3 years | ACCESS^40^; Non-ACCESS^49^
Peer support | Assessment of functioning of consumer case worker | Not applicable | Non-ACCESS^48^
Program implementation
Barriers and facilitators of program implementation | Barriers and facilitators of program implementation | Not applicable | Non-ACCESS^49^
Agency Integration | Agencies integration within existing system | Baseline | ACCESS^44^
Provider/staff experience
Provider perspective on program | Provider perspectives on program model | Not applicable | Non-ACCESS^49^
Employee training evaluation | Employee training evaluation; post-training attitude assessment | Not applicable | Non-ACCESS^48^
System Level
Cross-agency collaboration
Integration strategies | Systems integration strategies selected; novel systems integration strategies introduced; changes in strategies over time; implementation status of strategies | 5 years | ACCESS (Steadman, 2002^39^ Cocozza, 2000^41^ Rosenheck, 2002^40^)
Service Linkage | Reported patient referrals between service providers at each site within a multi-site program; Questions about referrals of patients, fund transfers, information sharing (5-point Likert scale); Integration across a system | 2 years | ACCESS^42,44^
Service maintenance
Service continuation | Number of core services continued post-funding by interagency site | 5 years | ACCESS^39^
Perceived service provision
Perceived accessibility of services for persons with experiences of homelessness and SMI | Robert Wood Johnson Foundation Program on Chronic Mental Illness | Not applicable | ACCESS^44^
Perceived coordination of services for persons with experiences of homelessness and SMI | Robert Wood Johnson Foundation Program on Chronic Mental Illness | Not applicable | ACCESS^44^

a Measure used in a VA study

b Could include emergency room or urgent care providers

Abbreviations: TCU=Texas Christian University; EHR=Electronic health record