# APPENDIX C INTERVENTION STRATEGIES TABLE

Study Country | Setting | Source of Participants (eg, Hospital, Criminal Justice) | Elements of Primary Care Integration | Core Disciplines Involved | #: Patient-level Intervention strategies | #: Clinic-level Intervention Strategies | #: System-level Intervention Strategies
492, Baker, 2018^32^ USA | Mental health clinic | NR | Enhanced referral | Psychiatrist; Nursing; | 6: Flexible appts; service navigation; interdisciplinary assessment; health education; crisis intervention; counseling/family therapy | 2: Specific employee training; Medication review/ management; | 1: Shared electronic health record
Corrigan, 2017^33^ USA | Not Reported | Clinics, homeless shelters | Standard referral | Not reported | 3: MI/goal setting; trauma informed care; harm reduction | 2: Specific training for employees; peer navigators | Not reported
Kelly, 2018^31^ USA | Mental health clinic | Multidisciplinary program (housing, MH, case management) | Standard referral | Behavioral health; Psychiatrist | 6: Health education; MI/goal setting; CBT; interdisciplinary assessment; service navigation; access to computers/ technology | 3: Specific employee training; Peer support/ community health workers; Medication review/ management; | 2: Shared electronic health record; Proactive monitoring system
McGuire, 2009^37^ USA | Primary care clinic | Housing program (homeless drop-in) | Interdisciplinary care planning; Co-location | Behavioral health; Psychiatrist; Nursing; Primary Care Provider; | 6: interdisciplinary assessment, service navigation, financial income, appoint prioritization, no waiting times, flexible schedule | 1: Specific employee training | Not reported
Patterson, 2012^47^ Canada | Not reported | Not reported | Standard performance metrics; Interagency collaborative body | Behavioral health; Psychiatrist; Nursing; Primary Care Provider | 2: Support for housing; income | Not reported | Not reported
RivasVasquez, 2009^36^ USA | Interdisciplinary clinic, Citrus Health Network community health center | Criminal justice | Interdisciplinary care planning; Co-location | Behavioral health; Primary Care Provider | 9: Health education; MI/goal-setting; stigma reduction; Justice system in-reach; Interdisciplinary intake; Service navigation; Transitions of care coordination; Transportation support; Housings support | 2: Specific employee training; Peer support/ community health workers; | Not reported
Rosenheck, 1993^45^ USA | Interdisciplinary clinic, HCMI clinics staff by 2 social workers and nurses | Community (street, soup kitchens); housing (shelters) | Enhanced referral | Nursing | 2: Service navigation; Housing support | Not reported | Not reported
Solomon, 1988^48^ USA | Housing services | Health clinic | Enhanced referral | Psychiatrist; Nursing; Primary Care Provider | 2: Crisis intervention; Empathic/stigma reduction | 2: Specific employee training; Peer support/ community health workers | Not reported
Stanhope, 2014^30^ USA | Housing services, community setting | Housing program | Interdisciplinary care planning | Primary Care Provider | 5: Health education; MI/goal setting; service navigation; financial housing support; no sobriety requirement | 1: Peer support/ community health workers | Not reported
Stergiopoul os, 2018 ^28^ Canada | Primary care clinic, mental health clinic | Hospitals discharging patients; homeless shelter sends recently discharged | Co-location, Enhanced referral | Not reported | 5: Supportive therapy; assertive outreach; interdisciplinary assessment; service navigation | 1: Peer support | Not reported
Stergiopoul os, 2015^34^ Canada | Housing services | Housing program (shelter) | Interdisciplinary care planning; Co-location; Standard referral | Psychiatrist; Primary Care Provider | 4: Health education; Service navigation; Housing support; Low barrier to care (on-site at shelter) | 1: Specific employee training | 1: Shared electronic health record
Stergiopoul os, 2012^49^ Canada | Interdisciplinary clinic | Shelters, drop-in centers, outreach teams, mental health teams, inpatient programs, criminal justice programs | Standard referral | Psychiatrist | 8: health education, crisis intervention, MI/goal setting, stigma, harm reduction, interdisciplinary assessment, service navigation, financial housing | 1: Specific employee training | Not reported
Weinstein, 2013^35^ USA | Primary care clinic, mental health clinic, Interdisciplinary clinic, housing services | NR | Co-location | Psychiatrist; Nursing; Primary Care Provider | 6: Health education; Assertive outreach; Interdisciplinary needs assessment; Service navigation; Housing support; Flexible appointment scheduling | 2: Peer support/ community health workers; Medication review/ management | 1: Proactive monitoring system
Weinstein, 2013^46^ USA | Interdisciplinary clinic, housing services | NR | Interdisciplinary care planning; Co-location; Enhanced referral | Psychiatrist; Nursing; Primary Care Provider | 4: Assertive outreach; Service navigation; Housing support; No sobriety/treatment requirements | Not reported | 2: Shared electronic health record; Standard performance metrics

Abbreviations: MI= Motivational interviewing; CBT= Cognitive behavioral therapy