# APPENDIX B STUDY CHARACTERISTICS TABLES

## ACCESS Studies: Federally Funded Demonstration Program

## Non-ACCESS Studies