# APPENDIX A SEARCH STRATEGIES

## Database: MEDLINE (via MEDLINE ALL, Ovid, 1946 to May 14, 2020)

Search date: 5/15/2020

Search Set | Search Strategy | Results
#1; Housing Status Concepts | exp Homeless Persons/ or (homeless or homelessness or “lack of housing” or squatter or squatters or “no fixed address” or roofless or “doubled up” or “doubled-up” or “rough sleep” or “rough sleeping” or “couch surfing” or “couch surf” or “couch surfer” or “couch surfers” or “supportive housing”).ti,ab. or ((street or transient or transients) adj2 (population or person or persons or people or peoples or individual or individuals or adult or adults or youth or youths or men or man or women or woman or dweller or dwellers)).ti,ab. or ((temporary or unstable or unstableness or instability or insecurity or inequality or vulnerable or vulnerability or non-permanent or non-permanent) adj2 (home or homes or house or houses or housing or accommodation or accommodations or apartment or apartments or shelter or shelters or sheltering or hostel or hostels or dwelling or dwellings)).ti,ab. | 15,634
#2; Primary Care Concepts | exp Primary Health Care/ or Physicians, Family/ or Physicians, Primary Care/ or General Practitioners/ or Family Practice/ or Community Health Services/ or Community Health Nursing/ or exp Community Health Centers/ or Family Nursing/ or Mobile Health Units/ or Health Services Accessibility/ or “Delivery of Health Care"/ or “Delivery of Health Care, Integrated"/ or (“primary care” or “primary health care” or “primary healthcare” or “health visit” OR “health visits” OR “health visitation” OR “health visitations” OR “wellness visit” OR “wellness visits” OR “wellness visitation” OR “wellness visitations” OR “wellness exam” OR “wellness exams” OR “wellness examination” OR “wellness examinations” OR “annual exam” OR “annual exams” OR “annual examination” OR “annual examinations” or (general adj (practice or practise or practices or practises or practician or practitioner or practitioner)) or (family adj (practice or practise or medicine or physician or physicians or doctor or doctors)) or (collaborative adj2 (care or model or models or practice or practice)) or (community adj (health or healthcare or nurse or nurses or nursing or outreach)) or ((community or neighbo?rhood) adj (“health center” or “health centers” or “health centre” or “health centres” or healthcenter or healthcenters or healthcentre or healthcentres)) or ((nurse or nurses or nursing) adj (family or practitioner or practitioners or primary or advance or advanced or practice or practiced)) or ((mobile or fixed) adj (“outreach program” or “outreach programs”)) or (mobile adj (hospital or hospitals or “health unit” or “health units” or “health van” or “health vans” or clinic or clinics)) or ((coordinate or coordinates or coordinated or coordinating or integrate or integrates or integrated or integrating or co-locate or co-locates or co-located or co-locating) adj3 (“health service” or “health services” or “health care” or healthcare)) or ((“health service” or “health services”) adj2 (accessibility or availability)) or ((healthcare or health care) adj2 (deliver or delivers or delivered or delivery)) or (“access to health care” or “access to healthcare”) or (integrated adj delivery adj (system or systems)) or ((“patient centered” or “patient-centered”) adj2 (“medical home” or “medical homes”)) or PCMH or (patient adj2 aligned adj2 (“care team” or “care teams” or “healthcare team” or “healthcare teams”)) or PACT or HPACT).ti,ab. | 590,937
#3; Veterans/ VA concepts | exp Veterans/ or exp “United States Department of Veterans Affairs"/ or exp Veterans Health/ or exp Veterans Health Services/ or (veteran or veterans or “VA health” or “VA healthcare” or “VA clinic” OR “VA clinics” or “VA administration”).ti,ab. | 39,737
#4 | 2 or 3 | 625,193
#5 | 1 and 4 | 3,594
#6 | 5 not (case reports or editorial or letter or comment).pt. | 3,371

## EMBASE (via Elsevier)

Search date: 5/15/2020

Search Set | Search Strategy | Results
#1; Housing Status Concepts | ’homelessness’/exp OR ‘homeless person’/exp or (homeless or homelessness or ‘lack of housing’ or squatter or squatters or ‘no fixed address’ or roofless or ‘doubled up’ or ‘doubled-up’ or ‘rough sleep’ or ‘rough sleeping’ or ‘couch surfing’ or ‘couch surf’ or ‘couch surfer’ or ‘couch surfers’ or ‘supportive housing’):ti,ab or ((street or transient or transients) NEAR/2 (population or person or persons or people or peoples or individual or individuals or adult or adults or youth or youths or men or man or women or woman or dweller or dwellers)):ti,ab or ((temporary or unstable or unstableness or instability or insecurity or inequality or vulnerable or vulnerability or nonpermanent or nonpermanent) NEAR/2 (home or homes or house or houses or housing or accommodation or accommodations or apartment or apartments or shelter or shelters or sheltering or hostel or hostels or dwelling or dwellings)):ti,ab | 19,446
#2; Primary Care Concepts | ’primary health care’/exp OR ‘general practitioner’/exp OR ‘general practice’/exp OR ‘community care’/de OR ‘community health nursing’/exp OR ‘community mental health center’/exp OR ‘family nursing’/exp OR ‘field hospital’/de OR ‘health care access’/de OR ‘health care delivery’/de OR ‘integrated health care system’/exp or (’primary care’ or ‘primary health care’ or ‘primary healthcare’ or ‘health visit’ OR ‘health visits’ OR ‘health visitation’ OR ‘health visitations’ OR ‘wellness visit’ OR ‘wellness visits’ OR ‘wellness visitation’ OR ‘wellness visitations’ OR ‘wellness exam’ OR ‘wellness exams’ OR ‘wellness examination’ OR ‘wellness examinations’ OR ‘annual exam’ OR ‘annual exams’ OR ‘annual examination’ OR ‘annual examinations’ or (general NEAR/1 (practice or practise or practices or practises or practician or practitioner or practitioner)) or (family NEAR/1 (practice or practise or medicine or physician or physicians or doctor or doctors)) or (collaborative NEAR/2 (care or model or models or practice or practice)) or (community NEAR/1 (health or healthcare or nurse or nurses or nursing or outreach)) or ((community or neighbo?rhood) NEAR/1 (’health center’ or ‘health centers’ or ‘health centre’ or ‘health centres’ or healthcenter or healthcenters or healthcentre or healthcentres)) or ((nurse or nurses or nursing) NEAR/1 (family or practitioner or practitioners or primary or advance or advanced or practice or practiced)) or ((mobile or fixed) NEAR/1 (’outreach program’ or ‘outreach programs’)) or (mobile NEAR/1 (hospital or hospitals or ‘health unit’ or ‘health units’ or ‘health van’ or ‘health vans’ or clinic or clinics)) or ((coordinate or coordinates or coordinated or coordinating or integrate or integrates or integrated or integrating or colocate or colocates or colocated or colocating) NEAR/3 (’health service’ or ‘health services’ or ‘health care’ or healthcare)) or ((’health service’ or ‘health services’) NEAR/2 (accessibility or availability)) or ((healthcare or ‘health care’) NEAR/2 (deliver or delivers or delivered or delivery)) or (’access to health care’ or ‘access to healthcare’) or (integrated NEAR/1 delivery NEAR/1 (system or systems)) or ((’patient centered’ or ‘patient-centered’) NEAR/2 (’medical home’ or ‘medical homes’)) or PCMH or (patient NEAR/2 aligned NEAR/2 (’care team’ or ‘care teams’ or ‘healthcare team’ or ‘healthcare teams’)) or PACT or HPACT):ti,ab | 745,422
#3; Veterans/ VA concepts | ’veteran’/exp OR ‘veterans health’/exp OR ‘veterans health service’/exp or (veteran or veterans or ‘VA health’ or ‘VA healthcare’ or ‘VA clinic’ OR ‘VA clinics’ or ‘VA administration’):ti,ab | 50,259
#4 | #2 OR #3 | 789,311
#5 | #1 AND #4 | 4,561
#6 | #5 NOT (’case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR [editorial]/lim OR ‘letter’/exp OR [letter]/lim OR ‘note’/exp OR [note]/lim OR [conference abstract]/lim OR ‘conference abstract’/exp OR ‘conference abstract’/it) | 3,452

## PsycINFO (via Ovid, 1806 to May Week 2 2020)

Search date: 5/15/2020

Search Set | Search Strategy | Results
#1; Housing Status Concepts | exp Homeless/ or (homeless or homelessness or “lack of housing” or squatter or squatters or “no fixed address” or roofless or “doubled up” or “doubled-up” or “rough sleep” or “rough sleeping” or “couch surfing” or “couch surf” or “couch surfer” or “couch surfers” or “supportive housing”).ti,ab. or ((street or transient or transients) adj2 (population or person or persons or people or peoples or individual or individuals or adult or adults or youth or youths or men or man or women or woman or dweller or dwellers)).ti,ab. or ((temporary or unstable or unstableness or instability or insecurity or inequality or vulnerable or vulnerability or nonpermanent or non-permanent) adj2 (home or homes or house or houses or housing or accommodation or accommodations or apartment or apartments or shelter or shelters or sheltering or hostel or hostels or dwelling or dwellings)).ti,ab. | 12,720
#2; Primary Care Concepts | exp Primary Health Care/ or Family Physicians/ or General Practitioners/ or Family Medicine/ or exp Community Mental Health Services/ or (“primary care” or “primary health care” or “primary healthcare” or “health visit” OR “health visits” OR “health visitation” OR “health visitations” OR “wellness visit” OR “wellness visits” OR “wellness visitation” OR “wellness visitations” OR “wellness exam” OR “wellness exams” OR “wellness examination” OR “wellness examinations” OR “annual exam” OR “annual exams” OR “annual examination” OR “annual examinations” or (general adj (practice or practise or practices or practises or practician or practitioner or practitioner)) or (family adj (practice or practise or medicine or physician or physicians or doctor or doctors)) or (collaborative adj2 (care or model or models or practice or practice)) or (community adj (health or healthcare or nurse or nurses or nursing or outreach)) or ((community or neighbo?rhood) adj (“health center” or “health centers” or “health centre” or “health centres” or healthcenter or healthcenters or healthcentre or healthcentres)) or ((nurse or nurses or nursing) adj (family or practitioner or practitioners or primary or advance or advanced or practice or practiced)) or ((mobile or fixed) adj (“outreach program” or “outreach programs”)) or (mobile adj (hospital or hospitals or “health unit” or “health units” or “health van” or “health vans” or clinic or clinics)) or ((coordinate or coordinates or coordinated or coordinating or integrate or integrates or integrated or integrating or co-locate or co-locates or co-located or co-locating) adj3 (“health service” or “health services” or “health care” or healthcare)) or ((“health service” or “health services”) adj2 (accessibility or availability)) or ((healthcare or health care) adj2 (deliver or delivers or delivered or delivery)) or (“access to health care” or “access to healthcare”) or (integrated adj delivery adj (system or systems)) or ((“patient centered” or “patient-centered”) adj2 (“medical home” or “medical homes”)) or PCMH or (patient adj2 aligned adj2 (“care team” or “care teams” or “healthcare team” or “healthcare teams”)) or PACT or HPACT).ti,ab. | 79,319
#3; Veterans/ VA concepts | Military Veterans/ or (veteran or veterans or “VA health” or “VA healthcare” or “VA clinic” OR “VA clinics” or “VA administration”).ti,ab. | 22,513
#4 | 2 or 3 | 100,280
#5 | 1 and 4 | 1,346
#6 | limit 5 to (“0100 journal” or “0110 peer-reviewed journal”) | 1,074