# REFERENCES

1 Lopez-Nava G, Sharaiha RZ, Vargas EJ, . Endoscopic Sleeve Gastroplasty for Obesity: a Multicenter Study of 248 Patients with 24 Months Follow-Up. Obes Surg. 2017;27(10):2649–2655.28451929
2 Campos GM, Khoraki J, Browning MG, Pessoa BM, Mazzini GS, Wolfe L. Changes in Utilization of Bariatric Surgery in the United States From 1993 to 2016. Ann Surg. 2020;271(2):201–209.31425292
3 Visscher TL, Seidell JC. The public health impact of obesity. Annu Rev Public Health. 2001;22:355–375.11274526
4 Hurt RT, Kulisek C, Buchanan LA, McClave SA. The obesity epidemic: challenges, health initiatives, and implications for gastroenterologists. Gastroenterol Hepatol (N Y). 2010;6(12):780–792.21301632
5 Bluher M. Obesity: global epidemiology and pathogenesis. Nat Rev Endocrinol. 2019;15(5):288–298.30814686
6 Albaugh VL, Abumrad NN. Surgical treatment of obesity. F1000Res. 2018;7.
7 O’Brien PE, DeWitt DE, Laurie C, . The Effect of Weight Loss on Indigenous Australians with Diabetes: a study of Feasibility, Acceptability and Effectiveness of Laparoscopic Adjustable Gastric Banding. Obes Surg. 2016;26(1):45–53.25990379
8 Stimac D, Klobucar Majanovic S, Belancic A. Endoscopic Treatment of Obesity: From Past to Future. Dig Dis. 2020:1–13.
9 World Health Organization. Obesity and overweight. https://www.who.int/news-room/fact-sheets/detail/obesity-and-overweight. Accessed 2022.
10 Department of Veterans Affairs Department of Defense. VA/DoD Clinical practice guidelines for screening and management of overweight and obesity. 2014.
11 American Society for Metabolic and Bariatric Surgery. Metabolic and Bariatric Surgery Fact Sheet https://asmbs.org/resources/metabolic-and-bariatric-surgery. Published 2021. Accessed 2022.
12 Sharaiha RZ, Hajifathalian K, Kumar R, . Five-Year Outcomes of Endoscopic Sleeve Gastroplasty for the Treatment of Obesity. Clin Gastroenterol Hepatol. 2021;19(5):1051–1057 e1052.33011292
13 Abu Dayyeh BK, Eaton LL, Woodman G, . A randomized, multi-center study to evaluate the safety and effectiveness of an intragastric balloon as an adjunct to a behavioral modification program, in comparison with a behavioral modification program alone in the weight management of obese subjects. Gastrointest Endosc. 2015;81(5):AB147.
14 Popov VB, Thompson CC, Kumar N, Ciarleglio MM, Deng Y, Laine L. Effect of Intragastric Balloons on Liver Enzymes: A Systematic Review and Meta-Analysis. Dig Dis Sci. 2016;61(9):2477–2487.27207181
15 Hedjoudje A, Abu Dayyeh BK, Cheskin LJ, . Efficacy and Safety of Endoscopic Sleeve Gastroplasty: A Systematic Review and Meta-Analysis. Clin Gastroenterol Hepatol. 2020;18(5):1043–1053.e1044.31442601
16 Abu Dayyeh BK, Kumar N, Edmundowicz SA, . ASGE Bariatric Endoscopy Task Force systematic review and meta-analysis assessing the ASGE PIVI thresholds for adopting endoscopic bariatric therapies. Gastrointest Endosc. 2015;82(3):425–438.e425.26232362
17 Begg CB, Mazumdar M. Operating characteristics of a rank correlation test for publication bias. Biometrics. 1994;50(4):1088–1101.7786990
18 Egger M, Davey Smith G, Schneider M, Minder C. Bias in meta-analysis detected by a simple, graphical test. BMJ. 1997;315(7109):629–634.9310563
19 The GRADE Working Group. http://www.gradeworkinggroup.org/. Published 2014. Accessed 2022.
20 Courcoulas A, Abu Dayyeh BK, Eaton L, . Intragastric balloon as an adjunct to lifestyle intervention: a randomized controlled trial. Int J Obes (Lond). 2017;41(3):427–433.28017964
21 Gómez V, Woodman G, Abu Dayyeh BK. Delayed gastric emptying as a proposed mechanism of action during intragastric balloon therapy: Results of a prospective study. Obesity (Silver Spring). 2016;24(9):1849–1853.27465076
22 Sullivan S, Swain J, Woodman G, . Randomized sham-controlled trial of the 6-month swallowable gas-filled intragastric balloon system for weight loss. Surg Obes Relat Dis. 2018;14(12):1876–1889.30545596
23 Raftopoulos Y, Davidson E, Robert K, . Weight Loss Comparison of an Intensive 16-Week Nutritional, Exercise and Behavior Modification Program with or without Swallowable Fluid-Filled Elipse Intragastric Balloon. J Am Coll Surg. 2019;229(4):e4.
24 Raftopoulos Y, Davidson E, Robert K, . An Intensive 52-week Nutritional, Exercise and Behavior Modification Program: Comparison With or Without the Elipse Intragastric Balloon. Surg Obes Relat Dis. 2019;15(10):S33.
25 Abu Dayyeh BK, Maselli DB, Rapaka B, . Adjustable intragastric balloon for treatment of obesity: a multicentre, open-label, randomised clinical trial. Lancet. 2021;398(10315):1965–1973.34793746
26 Ponce J, Quebbemann BB, Patterson EJ. Prospective, randomized, multicenter study evaluating safety and efficacy of intragastric dual-balloon in obesity. Surg Obes Relat Dis. 2013;9(2):290–295.22951075
27 Fuller NR, Pearson S, Lau NS, . An intragastric balloon in the treatment of obese individuals with metabolic syndrome: a randomized controlled study. Obesity (Silver Spring). 2013;21(8):1561–1570.23512773
28 Ponce J, Woodman G, Swain J, . The REDUCE pivotal trial: a prospective, randomized controlled pivotal trial of a dual intragastric balloon for the treatment of obesity. Surg Obes Relat Dis. 2015;11(4):874–881.25868829
29 Cheskin LJ, Hill C, Adam A, . Endoscopic sleeve gastroplasty versus high-intensity diet and lifestyle therapy: a case-matched study. Gastrointest Endosc. 2020;91(2):342–349.e341.31568769
30 Abd El Mohsen M, Gostout CJ, Bakr A, . Laparoscopic greater curvature plication (LGCP) vs. endoscopic sleeve gastroplasty (ESG): Similar efficacy with different physiology gastric plication. Obes Surg. 2017;27(1):630.27448233
31 Sullivan S, Swain JM, Woodman G, . Randomized sham-controlled trial evaluating efficacy and safety of endoscopic gastric plication for primary obesity: The ESSENTIAL trial. Obesity (Silver Spring). 2017;25(2):294–301.28000425
32 Novikov AA, Afaneh C, Saumoy M, . Endoscopic Sleeve Gastroplasty, Laparoscopic Sleeve Gastrectomy, and Laparoscopic Band for Weight Loss: How Do They Compare? J Gastrointest Surg. 2018;22(2):267–273.29110192
33 Lopez-Nava G, Asokkumar R, Bautista-Castaño I, . Endoscopic sleeve gastroplasty, laparoscopic sleeve gastrectomy, and laparoscopic greater curve plication: do they differ at 2 years? Endoscopy. 2021;53(3):235–243.32698234
34 Fiorillo C, Quero G, Vix M, . 6-Month Gastrointestinal Quality of Life (QoL) Results after Endoscopic Sleeve Gastroplasty and Laparoscopic Sleeve Gastrectomy: A Propensity Score Analysis. Obes Surg. 2020;30(5):1944–1951.31965488
35 Lopez-Nava G, Negi A, Bautista-Castaño I, Rubio MA, Asokkumar R. Gut and Metabolic Hormones Changes After Endoscopic Sleeve Gastroplasty (ESG) Vs. Laparoscopic Sleeve Gastrectomy (LSG). Obes Surg. 2020;30(7):2642–2651.32193741
36 Fayad L, Adam A, Schweitzer M, . Endoscopic sleeve gastroplasty versus laparoscopic sleeve gastrectomy: a case-matched study. Gastrointest Endosc. 2019;89(4):782–788.30148991
37 Benias P, Vegesna AK, Leung TM, . A retrospective study of weight and metabolic changes in patients with obesity (BMI≥30 kg/m2) after endoscopic sleeve gastroplasty (ESG) or laparoscopic sleeve gastrectomy (LSG). Diabetes. 2020;69.
38 Mohammed MA, Anwar R, Mansour AH, Elmasry E, Othman G. Effects of intragastric balloon versus conservative therapy on appetite regulatory hormones in obese subjects. Trends in medical research. 2014;9(2):58–80.
39 Thompson CC, Abu Dayyeh BK, Kushner R, . Percutaneous Gastrostomy Device for the Treatment of Class II and Class III Obesity: Results of a Randomized Controlled Trial. Am J Gastroenterol. 2017;112(3):447–457.27922026
40 Wilson EB, Noren E, Gruvaeus J, Paradis C. A comparative 100-participant 5-year study of aspiration therapy versus roux-en-y gastric bypass: 2nd and 3rd year results. Surg Obes Relat Dis. 2018;14(11):S15.
41 Sullivan S, Edmundowicz SA, Stein RI, Jonnalagadda SS, Mullady D, Klein S. Aspiration therapy is an effective endoscopic approach for treating obesity: results of a two-year clinical trial. Gastroenterology. 2012;142(5 SUPPL. 1):S78.
42 Ahmed HO, Ezzat RF. Quality of life of obese patients after treatment with the insertion of intra-gastric balloon versus Atkins diet in Sulaimani Governorate, Kurdistan Region, Iraq. Ann Med Surg. 2019;37:42–46.
43 Sadek R, Wassef A. Endoscopic sleeve gastroplasty versus laparoscopic longitudinal sleeve gastrectomy: A comparable outcome. Surg Obes Relat Dis. 2017;13(10):S7–S8.
44 Okamura K, Kanai S, Hasegawa M, Otsuka A, Oki S. Effect of electromyographic biofeedback on learning the short foot exercise. Journal of back and musculoskeletal rehabilitation. 2019;32(5):685–691.30636725
45 Mathus-Vliegen EMH, Alders PRH, Chuttani R, Scherpenisse J. Outcomes of intragastric balloon placements in a private practice setting. Endoscopy. 2015;47(4):302–307.25479562
46 Moore RL, Seger MV, Garber SM, . Clinical safety and effectiveness of a swallowable gas-filled intragastric balloon system for weight loss: consecutively treated patients in the initial year of U.S. commercialization. Surg Obes Relat Dis. 2019;15(3):417–423.30797717
47 Abeid M, Kaddah T, Zaitoun NA, Alsamman MA. Efficacy and Safety of Intragastric Balloon Placements in 1600 Case, an Experience from the Middle East. Obes Surg. 2019;29(7):2087–2091.30953338
48 Espinet Coll E, Nebreda Durán J, López-Nava Breviere G, . Multicenter study on the safety of bariatric endoscopy. Rev Esp Enferm Dig. 2017;109(5):350–357.28301947
49 Abu Dayyeh BK, Noar MD, Lavin T, . PIVOTAL RANDOMIZED-CONTROLLED TRIAL OF THE ADJUSTABLE (SPATZ-3)INTRAGASTRIC BALLOON SYSTEM FOR WEIGHT LOSS. Gastrointest Endosc. 2019;89(6):AB58–AB59.
50 Alqahtani A, Al-Darwish A, Mahmoud AE, Alqahtani YA, Elahmedi M. Short-term outcomes of endoscopic sleeve gastroplasty in 1000 consecutive patients. Gastrointest Endosc. 2019;89(6):1132–1138.30578757
51 Folini L, Veronelli A, Benetti A, . Liver steatosis (LS) evaluated through chemical-shift magnetic resonance imaging liver enzymes in morbid obesity; effect of weight loss obtained with intragastric balloon gastric banding. Acta Diabetol. 2014;51(3):361–368.24085682
52 Thompson CC, Abu Dayyeh BK, Kushnir V, . Aspiration therapy for the treatment of obesity: 4-year results of a multicenter randomized controlled trial. Surg Obes Relat Dis. 2019;15(8):1348–1354.31302000
53 Sander BQ, Marchesini C, Paiva DS, . Intragastric balloon: A large brazilian multicentric study over 10,000 cases and 20 years of experience. United European Gastroenterol J. 2017;5(5):A618.
54 Fuller NR, Lau NS, Denyer G, Caterson ID. An intragastric balloon produces large weight losses in the absence of a change in ghrelin or peptide YY. Clin Obes. 2013;3(6):172–179.25586733
55 Pryor A, Swain J, Woodman G, . A 6-month swallowable balloon system results in sustainable weight loss at 1 year: Results from a prospective, randomized sham-controlled trial. Surg Obes Relat Dis. 2016;12(7):S26–S27.
56 Russo T, Aprea G, Formisano C, . BioEnterics Intragastric Balloon (BIB) versus Spatz Adjustable Balloon System (ABS): Our experience in the elderly. Int J Surg. 2017;38:138–140.27353844
57 Salomone F, Currenti W, Magri G, Boskoski I, Zelber-Sagi S, Galvano F. Effects of intragastric balloon in patients with nonalcoholic fatty liver disease and advanced fibrosis. Liver international. 2021.
58 Lee YM, Low HC, Lim LG, . Intragastric balloon significantly improves nonalcoholic fatty liver disease activity score in obese patients with nonalcoholic steatohepatitis: a pilot study. Gastrointest Endosc. 2012;76(4):756–760.22840293
59 Chan DL, Cruz JR, Mui WL, Wong SKH, Ng EKW. Outcomes with Intra-gastric Balloon Therapy in BMI < 35 Non-morbid Obesity: 10-Year Follow-Up Study of an RCT. Obes Surg. 2021;31(2):781–786.33034015
60 Brethauer SA, Chand B, Schauer PR, Thompson CC. Transoral gastric volume reduction as intervention for weight management: 12-month follow-up of TRIM trial. Surg Obes Relat Dis. 2012;8(3):296–303.22178565
61 Sharaiha RZ, Kumta NA, Saumoy M, . Endoscopic Sleeve Gastroplasty Significantly Reduces Body Mass Index and Metabolic Complications in Obese Patients. Clin Gastroenterol Hepatol. 2017;15(4):504–510.28017845
62 Lassailly G, Caiazzo R, Buob D, . Bariatric Surgery Reduces Features of Nonalcoholic Steatohepatitis in Morbidly Obese Patients. Gastroenterology. 2015;149(2):379–388; quiz e315-376.25917783
63 Vilar-Gomez E, Friedman SL, Romero-Gomez M. Reply: To PMID 25865049. Gastroenterology. 2015;149(7):1988–1989.26515488
64 Wilding JPH, Batterham RL, Calanna S, . Once-Weekly Semaglutide in Adults with Overweight or Obesity. N Engl J Med. 2021;384(11):989.33567185
65 Badurdeen D, Hoff AC, Hedjoudje A, . Endoscopic sleeve gastroplasty plus liraglutide versus endoscopic sleeve gastroplasty alone for weight loss. Gastrointest Endosc. 2021;93(6):1316–1324.e1311.33075366
66 Fuller N, Pearson S, Lau N, . A prospective, randomised, controlled trial of the BioEnterics® Intragastric Balloon (BIB) in the treatment of obese individuals with metabolic syndrome. Obes Rev. 2010;11:436-.