# ACKNOWLEDGMENTS

The authors are grateful to Marika Booth for statistical analysis, Alireza Sedarat, MD and Erik Dutson, MD for conceptualization support, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Jason A. Dominitz, MD, MHS
  National Program Director
  National Gastroenterology and Hepatology Program Office
  Veterans Health Administration

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Luke Funk, MD, MPH, FACS
  Associate Professor, University of Wisconsin-Madison Department of Surgery
  Chief of General Surgery, William S. Middleton VA
  Madison, Wisconsin
- John Morton, MD, MPH, FACS
  Vice-Chair for Quality, Division Chief for Bariatric and Minimally Invasive Surgery and Professor in the Department of Surgery at the Yale School of Medicine
  New Haven, CT
- Violeta Popov, MD, PhD
  Assistant Professor, Department of Medicine at NYU Grossman School of Medicine
  New York, NY
- Shelby Sullivan, MD
  Associate Professor/Director of the Gastroenterology Metabolic and Bariatric Program, Medicine-Gastroenterology, University of Colorado, School of Medicine
  Denver, CO

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix B for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.