# DISCUSSION

## SUMMARY OF EVIDENCE BY KEY QUESTION

### Key Question 1

Treatment with IGBs was associated with significantly more weight loss compared to lifestyle therapy at multiple short- and intermediate-term follow-up time points (6 and 12 months). These results were consistent across RCTs and observational studies. Treatment with ESG was associated with significantly more weight loss compared to lifestyle therapy, again at 6- and 12-months follow-up. Treatment with ESG was associated with less weight loss than LSG; this conclusion is based solely on observational studies, although results are consistent. Treatment with the AspireAssist was associated with more weight loss than lifestyle therapy in 1 RCT. There was insufficient evidence on associations between treatments and QOL or HbA1C measures to reach conclusions. There are fewer studies assessing the durability of weight loss with endoscopic therapies, such as at 5 years or even 10 years following the intervention, than exist for some established bariatric surgeries (such as gastric bypass). One study by Chan et al compared IGB to sibutramine, a now discontinued weight loss medication. This RCT found no difference between IGB and sibutramine weight loss at 10 years.^59^

### Key Question 2

All studies comparing endoscopic bariatric therapy to lifestyle reported more total complications and 30-day readmission or re-intervention rates in the intervention arm, which is expected given these patients underwent an invasive intervention. There were no or borderline statistically significant differences in total complications between patients treated with LSG compared to ESG, although all studies reported more complications with LSG.

### Key Question 3

Regarding demographic or interventional factors that improve weight loss outcomes or increase risk for adverse events, there was insufficient evidence to answer this question. It is possible that certain patient variables may contribute to more profound weight loss post-therapy. A multicenter study asserted that younger patients may have more profound weight loss 1 year after gastric plications.^60^ This study was not included in this review because the plications were performed with the RESTORe suturing system, which is no longer widely used. However, some have speculated that younger age at the time of intervention may allow for shortened recovery and quicker introduction of exercise back into the lifestyle regimen post-therapy. Higher initial BMI may be associated with more profound weight loss after intervention; however, it is unclear if this would translate to a substantial difference in %TBWL. Patients with underlying gastric motility disorders are poorer candidates for endoscopic therapy given higher complication rates of nausea, vomiting, and oral intolerance due to potentiating delayed gastric emptying with ESG or IGB therapy.^21^

## LIMITATIONS

### Publication Bias

In the few places where we were able to statistically test for the possibility of publication bias, no such evidence was found. It is possible, however, that the tests employed were underpowered in the present analyses, as is commonly the case, and the large p-values produced by the tests are suggestive of low statistical power. Nevertheless, we feel it is unlikely that there exist high-quality randomized trials or comparative observational studies of endoscopic bariatric therapies compared to surgical or pharmacologic therapies that were not identified and similarly escaped detection by other experts in this field. On the other hand, it is likely that a large volume of case series on endoscopic bariatric therapies from individual practices and institutions exists but has not been published, especially as endoscopic bariatric therapies are often paid for out of pocket, and the available literature likely represents only a small fraction of what could have been known using case series. The decision to exclude case series was due to concerns about limited follow-up and single-institution bias present in studies of this type.

### Study Quality

The RCTs were judged to have low risk of bias for outcomes such as weight loss, HbA1c, QOL, and complications. True blinding of participants is difficult with bariatric interventions, and even with a high-quality sham swallowable balloon protocol, it is likely patients were able to feel if they were given an IGB or placebo. Additionally, blinding of outcome assessment was rarely discussed, and it is unclear how weight was reported; it is also unlikely participants could remain blinded to changes in their weight. Incomplete outcome data remains a difficult challenge in bariatric studies, as was frequently seen in these RCTs with suboptimal long-term follow-up. The observational studies were judged to have moderate risk of bias due to their non-random assignment of treatments, which increases risk of procedure selection bias. Many of the observational studies did not state how patients were directed towards either endoscopic or surgical bariatric interventions, causing a risk of selection bias. However, of these studies, 4 used propensity matching to mitigate selection bias, which corresponded to a reduction in the rating of this risk from high to moderate.

### Methodological Inconsistency

Included studies compared IGB to lifestyle therapy, ESG to lifestyle therapy, ESG to LSG, ESG to AGB, AspireAssist to lifestyle therapy, and AspireAssist to RYGB. Of these, only IGB versus lifestyle, ESG versus lifestyle, ESG versus LSG, and AspireAssist versus lifestyle were examined in multiple studies. Although we evaluated each comparison group separately, there were remaining inconsistencies among studies within comparison groups. For example, studies varied in choice of intragastric balloon (Obalon, Orbera, Reshape, Spatz, and Ellipse were all used); balloon placement (some balloons were endoscopically placed, whereas others were swallowable capsules); and, in the case of ESG, some procedures were traditional ESG whereas others were the Primary Obesity Surgery Endolumina (POSE) method. Additionally, lifestyle therapy represents a wide range of interventions, from providing patients with reading regarding healthy lifestyle choices, to scheduled meetings with registered dieticians, physical therapists, and psychologists.

Patient population such as age, BMI, and gender were largely similar among intervention and control groups. However, especially in endoscopic versus surgical review studies, the patient population undergoing surgery tended to have more significant metabolic comorbidities, such as higher rates of diabetes, hypertension, and super obesity, introducing heterogeneity into these comparisons in both outcomes and adverse events. This phenomenon was seen in nearly every identified endoscopic versus surgery study.

Although obesity intervention outcomes, such as weight loss and HbA1c, are largely standardized, adverse event reporting appeared more inconsistent. Multiple articles reported no adverse events among their intervention cohorts, which is possibly due to a true lack of adverse events or a study-specific definition of threshold of adverse event severity. Other studies had lower thresholds for adverse event reporting but may have had differing definitions of adverse events such as dehydration, abdominal pain, and dyspepsia.

### Applicability

No studies were specific to VA populations. The applicability of these results to VA populations may depend on both the similarity of the patients studied in the trials to VA patients as well as the experience of the gastroenterologists performing endoscopic bariatric therapies in the examined studies compared to VA team experience. Additionally, management of bariatric patients requires extensive multidisciplinary care and follow-up, as often represented by the control group of lifestyle treatment. However, the benefits of endoscopic bariatric therapies may still be realized or even amplified given the population health differences among the general population in comparison to the VA, as the VA population has greater burden of comorbidities than the general population. Further studies are warranted to examine efficacy of endoscopic bariatric therapies in the VA system. Endoscopic bariatric procedures, though still representing a small fraction of all bariatric procedures performed in the US, are becoming more widely adopted and studied, which will likely translate to the VA setting.

## FUTURE RESEARCH

The history of weight loss interventions is one of innovation and dissemination prior to evaluation. Vertical banded gastroplasty, prior versions of the gastric balloon, and the combination medication of fenfluramine and phentermine (“Fen-Phen”) are all examples of interventions developed and widely used before sufficient studies had been done to establish their risk-benefit profile. These interventions have since been removed following research showing the benefit not to be worth the risk. It would behoove the VA to not repeat this history, and to adequately assess new interventions before they are made widely available. Several research gaps are highlighted below.

First, a majority of the endoscopic studies have follow-up timelines that terminate between the 1- to 2-year mark. There are 2 studies at present with follow up of >4 years.^52,61^ Compared to the existing literature on bariatric surgeries, with some reporting follow-up data spanning past a decade, these novel endoscopic therapies lack long-term data. Studies are necessary to firmly establish the durability of weight loss following endoscopic therapy including rates of repeat or alternative endoscopic or surgical interventions due to weight recidivism.

Second, there are no high-quality RCTs comparing endoscopic bariatric procedures to surgery. We identified 3 propensity-matched trials comparing ESG to surgical procedures, mostly LSG.^29,34,36^ We recognize that performing such studies has logistical limitations, but these head-to-head trials are essential. Currently, bariatric surgery is indicated per guidelines for patients with BMI >35 with at least 1 comorbid condition or BMI > 40. However, given the millions of patients who qualify under these parameters and the limited number of bariatric surgeons, endoscopic therapies could be an alternative. Trials enrolling patients with the above BMI criteria to compare effectiveness of endoscopic therapy to surgery also need to assess impact on comorbid conditions, along with long-term cost benefits. Financial impacts on closed health care systems, such as the VA or Kaiser, offer an important opportunity for comprehensive assessments of long-term care costs related to obesity treatments.

Third, additional direct endoscopic and surgical comparisons of post-procedure complications and adverse events are also necessary to improve patient selection for certain procedures. For example, RCTs are scarce in the “super obese” population (BMI >50), who have elevated risk profiles given their baseline comorbidities and anesthesia requirements. These patients theoretically would benefit more from the aggressive mean percent weight loss provided by the surgical interventions, but greater understanding is needed of the perioperative risks and adverse events associated with surgery compared to IGB or ESG as primary therapy to better weigh risks against the extent of potential weight loss.

Additional dedicated studies are required in other subpopulations of patients:

A. Class I Obesity. Patients with class I obesity (BMI 30-35) are not current candidates for bariatric surgery. However, data suggest early targeted intervention prior to the development of comorbid conditions should be a goal both for morbidity prevention and decreasing health care expenditures. In these patients, comparative trials of the various endoscopic options as well as medications will be valuable.
B. Underserved populations. Given the financial limitations with endoscopic bariatric therapies, largely due to lack of insurance coverage, the studied patient populations for most trials are primarily privately insured and white, as seen in Appendix G. More research is needed on the effectiveness and risks of all bariatric interventions in underserved and/or underrepresented populations.
C. Patients with obesity-related comorbid conditions such as diabetes, hypertension, non-alcoholic fatty liver disease. Sharaiha et al demonstrated significant reduction in hypertension, lipid panel, ALT as marker for fatty liver, and HbA1c at the 12-month timepoint following ESG, with sustained results up to 5 years post-procedure.^61^ Other available evidence suggests that that as little as 10% TBWL improves metabolic factors including markers for fatty liver disease.^62,63^ Studies are required to distinguish which endoscopic bariatric therapies can achieve these outcomes.
D. VA patients. There are currently no studies evaluating endoscopic therapies in the VA population.
E. Bridging therapy. We did not include studies assessing the efficacy of endoscopic bariatric therapy as a bridge to definitive treatment. Studies have described using IGB as a bridge to bariatric surgery, and it remains to be determined if this use reduces cost or adverse events.

Fourth, there are limited data evaluating the effectiveness of medications on weight loss when combined with endoscopic therapy. A recently published clinical trial demonstrated optimistic results with semaglutide use in patients, with obesity resulting 15% mean TBWL.^64^ There is a single study, which was excluded from our analysis due to lack of a non-endoscopic comparative arm, which demonstrated enhanced weight loss of +4% TBWL at the 4- and 7-month marks when ESG was combined with liraglutide as compared to ESG alone.^65^ Prior to any invasive procedure including endoscopy, patients should be trialed on pharmacologic management if tolerated. Many patients therefore will present for endoscopic therapies while on medications such as phentermine, orlistat, liraglutide, or semaglutide. Further studies evaluating efficacy of combination therapy are needed to assist in management of patients with obesity.

Fifth, because there are multiple bariatric endoscopy devices in development for future trials or FDA approval, standardization of primary outcomes (%TBWL, % EBWL, percentage of patients achieving >10% EBWL, percentage of patients achieving >25% EBWL, etc) would be beneficial to evaluate efficacy across studies. The same consideration arises when evaluating secondary outcomes associated with resolution of comorbid conditions.

## CONCLUSIONS

In summary, the endoscopic therapies IGB, ESG, and AspireAssist are associated with greater short- and intermediate-term weight loss in patients with obesity compared to lifestyle management alone. However, various complications are also more likely in patients treated with endoscopic therapies than with lifestyle management. No long-term studies of weight loss have been published. The degree of weight loss with endoscopic therapies is likely less than more invasive surgical interventions, but with fewer adverse events. The field of endoscopic bariatric therapy continues to innovate and expand, with multiple devices in the pipeline for FDA approval. The MERIT trial, a multicenter randomized trial evaluating ESG vs lifestyle, reported initial 1-year follow-up data in late 2021. As the field continues to grow, future research should include more robust RCTs or well-designed prospective matched studies with adequate power and follow-up to assess long-term weight loss and the effects on obesity-related comorbid conditions.