# RESULTS

## LITERATURE FLOW

The literature flow diagram (Figure 2) summarizes the results of the study selection process (full list of excluded studies available in Appendix B).

Figure 1 Literature Flowchart

## LITERATURE OVERVIEW

The literature search identified 3,541 potentially relevant citations (including 1 recommended by a subject matter expert), 500 of which were included at the abstract screening level. From these, a total of 385 abstracts were excluded for the following reasons: study design (N = 276), no outcomes (N = 53), bridging therapy (N = 24), duplicate (N = 22), modified procedures (N = 3), adjunct therapies (N = 2), pediatric (N = 2), procedure type not included (N = 2), and no data available (N = 1). This left 115 publications for full-text review, of which 79 publications were excluded for the following reasons: study design (N = 19), unavailable (N = 11), procedure type not included (N = 10), adjunct therapies (N = 8), modified procedures (N = 7), non-bariatric outcomes (N = 6), sample size (N = 6), no data available (N = 4), short follow-up (N = 4), duplicate data (N = 3), and bridging therapy (N = 1). A full list of excluded studies from the full-text review is in Appendix I. A total of 36 publications were identified at full-text review as meeting initial inclusion criteria. Descriptions of included publications are available in the Evidence Table (Appendix G).

### Intragastric Balloon

A total of 12 RCTs were identified, all of which compared IGB to lifestyle therapy. An additional 3 observational studies were identified comparing IGB to lifestyle therapy.

### Endoscopic Sleeve Gastroplasty

One RCT was identified comparing ESG to lifestyle therapy. An additional 11 observational studies were identified, of which 5 compared ESG to lifestyle therapy, 1 compared to AGB, and 7 compared ESG to LSG (1 study compared ESG to both AGB and LSG).

### Aspiration Therapy

A total of 3 RCTs were identified that compared AspireAssist to lifestyle therapy. One additional observation study compared AspireAssist to RYGB.

### Risk of Bias

For the RCTs, the most common sources of bias were lack of blinding of participants and personnel, incomplete outcome data, and blinding of outcome assessment. All studies were high risk of bias in at least 1 domain. For the observational studies, the most common sources of bias were bias due to confounders, selection of participants, missing data, and measurement of outcomes. All but one observational study has unknown or high risk of bias in at least 1 domain.

## KEY QUESTION 1 What is the comparative effectiveness of endoscopic bariatric interventions versus lifestyle interventions or bariatric surgery?

### 6 Month Total Body Weight Loss

A total of 10 studies compared %TBWL with IGB to control groups at 6 months (Figure 2).^13,20–28^ All of these studies compared IGB to lifestyle; 7 were RCTs and 3 were observational studies. All of these studies but 1 found significantly greater %TBWL in patients treated with IGB. The size of weight loss benefit was mostly similar between studies, with 95% CIs for the results overlapping in 9 of the 10 studies. We pooled the 7 RCTs in a random-effects meta-analysis (Figure 3). The pooled estimate of the mean difference in %TBWL at 6 months was 6.37% (95% CI [3.94, 8.80]). There was no evidence of publication bias (Egger’s test p = 0.903, Begg’s test p = 0.239). For the 3 observational studies, the random effect pooled estimate of mean difference in %TBWL at 6 months was 7.37% (95% CI [6.36, 8.39]), favoring treatment with balloon. There was no evidence of publication bias (Egger’s test p = 0.595, Begg’s test p = 1).

A total of 9 studies compared %TBWL with ESG to control groups at 6 months (Figure 2).^29–37^ One RCT and 2 observational studies^29–31^ compared ESG to lifestyle, and all found significantly greater %TBWL in the patients treated with ESG. The size of the weight loss benefit was very different in the 3 studies, with the 95% CIs for the results non-overlapping. The 1 study comparing ESG to laparoscopic adjustable gastric banding (LAGB) reported no significant differences in total body weight loss at 6 months. Six observational studies compared ESG to LSG at 6 months.^32–37^ These studies all reported significantly greater total body weight loss in the patients treated with LSG. We pooled these 6 observational studies in a random-effects meta-analysis (Figure 4). The pooled estimate of the mean difference in %TBWL at 6 months was 10.44% (95% CI [6.08, 14.80]), favoring treatment with LSG. There was no evidence of publication bias (Egger’s test p = 0.691, Begg’s test p = 0.817).

No studies compared AspireAssist %TBWL at the 6-month interval.

### 6 Month Excess Body Weight Loss

A total of 6 studies compared %EBWL with IGB to control groups at 6 months (Figure 5).^20,22,26–28,38^ All of these studies compared IGB to lifestyle, and all were RCTs. All of these studies but 1 found significant %EBWL in patients treated with IGB at 6 months. The size of weight loss benefit was mostly similar between studies, with 95% CIs for the results overlapping across all studies. A random-effects meta-analysis was performed examining %EBWL after IGB versus lifestyle (Figure 6). The pooled estimate of the mean difference in %EBWL at 6 months was 17.11% (95% CI [11.65, 22.57]). There was no evidence of publication bias (Egger’s test p = 0.618, Begg’s test p = 0.333).

A total of 2 studies compared excess body weight loss with ESG to control groups at 6 months: 1 RCT comparing ESG to lifestyle and 1 observational study comparing ESG to LSG.^31,34^ The study comparing ESG to lifestyle found significantly superior %EBWL in patients treated with ESG, whereas the observational study comparing ESG to LSG found significant %EBWL with LSG compared to ESG.

No studies compared AspireAssist %EBWL at the 6-month interval.

Figure 2 Total Body Weight Loss at 6 Months for Bariatric Endoscopic Procedures Compared to Lifestyle or Surgery

Abbreviations. %TBWL=mean percent total body weight loss; ESG=endoscopic sleeve gastroplasty; LAGB=laparoscopic adjustable gastric banding; LSG=laparoscopic sleeve gastrectomy.

Figure 3 Meta-analysis of IGB versus Lifestyle for the Outcome of Total Body Weight Loss at 6 Months

Figure 4 Meta-analysis of ESG versus LSG for the Outcome of %TBWL at 6 Months

Abbreviations. ESG=endoscopic sleeve gastroplasty; LSG=laparoscopic sleeve gastrectomy.

Figure 5 Excess Body Weight Loss at 6 Months for Bariatric Endoscopy as Compared to Lifestyle or Surgery

Abbreviations. %EWL=excess weight loss; ESG=endoscopic sleeve gastroplasty; LSG= laparoscopic sleeve gastrectomy.

Figure 6 Meta-analysis of Intragastric Balloon versus Lifestyle for the Outcome of %EBWL at 6 Months

### 12 Month Total Body Weight Loss

A total of 5 studies compared ESG to control groups at 12 months (Figure 7).^29,31–33,37^ Two studies compared ESG to lifestyle.^29,31^ Both of these studies found significantly greater %TBWL in the patients treated with ESG. One study compared ESG to LAGB, reporting significant differences in weight loss at 12 months with those treated with the gastric band.^32^ Three observational studies compared ESG to LSG at 12 months.^32,33,37^ These studies reported significantly greater %TBWL in the patients treated with LSG.

A total of 6 studies compared IGB to lifestyle at 12 months, 4 of which were RCTs.^13,20,21,24,26,27^ All studies except 1 RCT reported significant %TBWL with IGB compared to control. Of these studies, 4 used the Orbera endoscopically placed balloon, 1 reported results from the swallowable Ellipse balloon, and 1 study reported results with the Reshape dual balloon. The Reshape dual balloon result was the only trial not to be significant. We pooled these 4 RCTs in a random-effects meta-analysis (Figure 9). The pooled estimate was 4.13% (95% CI [2.99, 5.27]. There was no evidence of bias (Egger’s test p = 0.198, Begg’s test p = 0.469)

A total of 3 studies compared AspireAssist to control at 12 months, 1 of which was an RCT.^39–41^ Two RCTs compared longitudinal outcomes from AspireAssist to lifestyle therapy at 12 months, both reporting significant %TBWL with aspiration therapy versus control.^39,41^ One observational study compared AspireAssist to RYGB.^40^ This study demonstrated significantly more weight loss at 12 and 24 months with RYGB compared to AspireAssist.

### 12 Month Excess Body Weight Loss

A total of 4 studies compared %EBWL with IGB versus lifestyle at 12 months, all of which were RCTs (Figure 8).^20,26,27,38^ Of these studies, all but 1 demonstrated significant excess body weight loss at 12 months, and all 95% CIs overlapped.

One study reported %EBWL after ESG vs lifestyle therapy.^31^ This RCT reported statistically greater excess body weight loss at 12 months with ESG compared to control.

A total of 3 studies compared %EBWL with aspiration therapy to control at 12 months.^39–41^ Two RCTs compared AspireAssist to lifestyle, both reporting significantly increased %EBWL with aspiration therapy at 12 months.^39,41^ One observational study compared aspiration therapy to RYGB and reported significantly greater %EBWL at 12 months with RYGB compared to AspireAssist.^40^

Figure 7 Total Body Weight Loss at 12 Months for Bariatric Endoscopy as Compared to Lifestyle or Surgery

Abbreviations. %TBWL=mean percent total body weight loss; ESG=endoscopic sleeve gastroplasty; LAGB=laparoscopic adjustable gastric banding; LSG=laparoscopic sleeve gastrectomy.

Figure 8 Excess Body Weight Loss at 12 Months for Bariatric Endoscopic Procedures as Compared to Lifestyle or Surgery

Abbreviations. %EWL=excess weight loss; ESG=endoscopic sleeve gastroplasty; RYGB=Roux-en-Y gastric bypass.

Figure 9 Meta-analysis of IGB versus Lifestyle Outcome %TBWL at 12 Months

### Quality of Life Outcomes (Table 1)

#### IGB versus Lifestyle

One study reported quality of life (QOL) outcomes at both 6 and 12 months.^20^ This study found mean difference in IWQOL-Lite scores 7.5 points greater at 6 months and 6.4 points greater at 12 months after IGB compared to lifestyle treatment, but a confidence interval could not be determined (higher scores indicate better QOL).

#### ESG versus Lifestyle

One study reported QOL outcomes at 6 months, and 1 reported QOL outcomes at 12 months.^31,42^ Courcoulos et al found mean difference in IWQOL-Lite scores 3.11 points greater after 6 months and 3.88 points greater at 12 months after ESG compared to lifestyle treatment. This study found significantly higher QOL at 12 months compared to lifestyle. Ahmed et al found significantly higher risk differences of increased QOL in the balloon group at 6 months.

#### ESG versus LSG

Two studies reported QOL outcomes at 6 months.^34,43^ One study reported no significant difference in GIQOL scores between the 2 procedures.^34^ Another study reported 7.9% less improvement in QOL after ESG compared to LSG when subjectively rated on a scale of 1-10 at 6 months.^43^ This result was not statistically significant in 1 study, and in the other, no confidence interval could be determined.

Table 1 Hemoglobin A1c and Quality of Life Outcomes for Bariatric Endoscopic Procedures Compared to Lifestyle or Surgery

| HbA1c; Negative is better for endoscopic treatment; MD [95% CI] | Quality of Life; Positive is better for endoscopic treatment; MD [95% CI]
IGB vs Lifestyle
Abu Dayyeh, 2021, 9 mo (RCT) | −0.73 [−1.49, 0.02]^a^
Sullivan 2018, 6 mo (RCT) | 0.00 [−0.14, 0.14] | —
Courcoulos 2017, 6 mo (RCT) | — | 7.5 [NR]
Courcoulos 2017, 12 mo (RCT) | — | 6.40 [NR]
ESG vs Lifestyle
Ahmed 2019, 6 mo (RCT) | | 0.13 [0.02, 0.231]^c^
Sullivan 2017, 6 mo (RCT) | −0.03 [−0.9, 0.04] | —
Sullivan 2017, 12 mo (RCT) | −0.03 [−0.11, 0.05] | 2.9 [1.6, 4.2]
AspireAssist vs Lifestyle
Thompson 2017, 12 mo (RCT) | −0.14 [NR] | —
ESG vs LSG
Benais 2020, 12 mo (Obs) | −7.7 [−11.0, −4.8]^b^
Fiorillo 2020, 6 mo (Obs) | — | 1.00 [−8.6, 10.64]
Sadek 2017, 6 mo (Obs) | — | 7.9 [NR]

Notes.

a Only among those with type 2 diabetes and baseline HbA1c >7.5%.

b Mean difference percent change from baseline.

c Risk difference (different between percent reporting high QOL).

Abbreviations. ESG=endoscopic sleeve gastroplasty; IGB=intragastric balloon; LSG=laparoscopic sleeve gastrectomy.

### Hemoglobin A1c (Table 1)

#### IGB versus Lifestyle

Two studies reported changes in HbA1c after IGB.^22,25^ These studies found no significant differences in HbA1c after IGB compared to lifestyle.

#### ESG versus Lifestyle

One study reported changes in HbA1c after ESG compared to lifestyle.^31^ At both 6 and 12 months, there was no significant improvement in HbA1c compared to lifestyle therapy.

#### AspireAssist versus Lifestyle

One study reported changes in HbA1c after AspireAssist compared to lifestyle.^39^ This study reported a 12-month improvement in HbA1c 0.14 mg/dL greater after aspiration therapy compared to lifestyle, but statistical significance could not be calculated.

#### ESG versus LSG

One study reported changes in HbA1c after ESG compared to LSG.^37^ This study reported significantly greater mean percent decrease in HbA1c after ESG compared to LSG.

## KEY QUESTION 2 What are the comparative harms of endoscopic bariatric interventions versus lifestyle interventions or bariatric surgery?

Reporting of details of procedural adverse events was inconsistent across studies, limiting interpretation of relative harm when comparing techniques.

### Total Complications

A total of 12 studies reported total complication rates, defined as any complication in any patient (Figure 10, Table 2).^20,22,25,26,28,29,31–34,36,39^ One randomized trial comparing AspireAssist to lifestyle reported statistically significantly fewer complication rates with lifestyle therapy.^39^ Five randomized trials looking at IGB versus lifestyle all demonstrated statistically significantly fewer complications with lifestyle therapy.^20,22,25,26,44^ Two studies comparing ESG versus lifestyle found significantly fewer complication rates with lifestyle therapy.^29,31^ There were 4 observational studies focusing on ESG compared to LSG.^32–34,36^ Three of these studies reported no difference in complications between ESG and LSG, while 1 reported significantly higher rates of complications with ESG compared to LSG. A total of 2 case series reported total complication rates after IGB of 5.9% and 14.3%, respectively.^45,46^ One study reported complication rates after IGB in terms of Clavien-Dindo classification, reporting an 89.3% rate of Grade 1 complications, 10% rate of grade 2 complications, and 0.7% rate of grade 3 complications.^47^ Another case series reported major complication rates of 0.83% with IGB.^48^ No large volume case series reported total complication rates after ESG or AspireAssist.

A total of 4 studies reported total complication rates at 12 months.^29,31,32,39^ The 3 studies comparing intervention to lifestyle, ESG and AspireAssist, all reported significantly higher complication rates with intervention compared to lifestyle.^29,31,39^ The 1 study comparing ESG to LSG noted significantly higher complication rates with LSG compared to ESG.^32^

### 30-day Readmissions

The 1 study comparing intervention versus lifestyle therapy that assessed readmissions between groups noted higher 30-day readmission rates with IGB placement compared to lifestyle.^22^

A total of 3 studies compared 30-day readmissions between ESG and LSG, and none found significant differences in 30-day readmissions between the groups.

### 30-day Reinterventions

One study reported 30-day reintervention rates comparing IGB to lifestyle, reporting no differences. However, there is low confidence in this finding given the number of patients requiring premature balloon removal noted in other studies.^40^ One study of AspireAssist reported that there was 1 reintervention out of a trial of 137 patients who received AspireAssist therapy due to a skin port malfunction.^49^ Two studies compared 30-day reintervention rates between ESG and LSG, 1 noting no difference between the groups and the other noting fewer 30-day reinterventions amongst ESG compared to LSG.^32,36^ One case series reported a 30-day reintervention rate of 2.4%.^50^

### Abdominal Pain

Four studies compared patient-reporting of abdominal pain between IGB and lifestyle.^20,22,27,40^ Three studies noted significantly higher reporting of abdominal pain among IGB patients compared to lifestyle, while the third reported no abdominal pain among its cohort. One study compared patient reporting of abdominal pain between AspireAssist and lifestyle therapy, noting a higher rate of abdominal pain among patients receiving aspiration therapy compared to lifestyle. No studies compared abdominal pain reporting after ESG to LSG. One case series reported a 5.29% incidence of abdominal pain after IGB.^46^

### Gastric Ulceration

A total of 3 studies compared rates of gastric ulceration between IGB and lifestyle,^22,28,49^ all reporting significantly higher rates among IGB patients compared to lifestyle. One study compared rates of gastric ulceration in ESG patients to lifestyle, also noting higher rates with intervention.^51^ No studies reported rates of gastric ulceration compared to LSG or with aspiration therapy. Two case series reported rates of gastric ulceration after IGB placement as 0.82% and 0.9%, respectively.^45,46^

### Bleeding

One study reported higher rates of bleeding after IGB compared to lifestyle, although not statistically significant.^22^ One study reported significantly higher rates of bleeding after ESG compared to lifestyle.^31^ One study reported bleeding rates after aspiration therapy, finding no significantly different rates of bleeding amongst aspiration therapy compared to lifestyle.^52^ Three studies compared bleeding rates between ESG and LSG, all finding no significantly different rates of bleeding between interventions.^34–36^ Two case series reported rates of bleeding after IGB placement as 0.01% and 0.6%, respectively.^45,53^ One case series reported bleeding rates of ESG as 0.7%.^50^

### Gastroesophageal Reflux Disease (GERD)

One study compared GERD rates between IGB and lifestyle, finding significantly higher rates of GERD after IGB.^20^ One study compared GERD rates between ESG and lifestyle, finding no significant differences between interventions.^31^ A total of 2 studies compared rates of GERD between ESG and LSG, 1 finding no significant difference while another found less GERD after ESG compared to LSG.^34,36^ One case series reported a rate of GERD after IGB placement of 0.82%.^46^

### Nausea

Four studies compared nausea rates between IGB and lifestyle, finding significantly higher rates of nausea after IGB.^20,22,25,27^ One study compared nausea rates between ESG and lifestyle, finding significantly higher rates of nausea after ESG.^31^ One case series reported a rate of nausea after IGB placement of 63%.^46^ One additional case series reported nausea rates after ESG as 92.4%.^50^

### Vomiting

Four studies compared vomiting rates between IGB and lifestyle, finding significantly higher rates of vomiting after IGB.^20,22,25,27^ One study compared vomiting rates between ESG and lifestyle, finding significantly higher rates of vomiting after ESG.^31^ One study compared vomiting rates after AspireAssist compared to lifestyle, finding significantly higher rates after AspireAssist.^52^ A total of 2 studies compared vomiting rates between ESG and LSG, one finding significantly higher rates after ESG and another finding no significant difference.^32,36^ One case series reported vomiting rates after IGB placement as 31%.^46^

### Dehydration

Four studies compared dehydration rates between IGB and lifestyle therapy, 2 finding significantly higher rates of dehydration after IGB while the other 2 found no significant difference.^20,22,25,27^ One study compared dehydration rates after ESG versus lifestyle therapy, finding no significant difference in rates.^29^ One study compared dehydration rates after ESG versus LSG, finding no significant difference.^36^ Two case series reported rates of dehydration after IGB placement of 0.07% and 0.2%, respectively.^45,46^

Figure 10 Total Complications for Bariatric Endoscopic Procedures Compared to Lifestyle or LSG

Abbreviations. %TBWL=mean percent total body weight loss; ESG=endoscopic sleeve gastroplasty; LAGB=laparoscopic adjustable gastric banding; LSG=laparoscopic sleeve gastrectomy.

Table 2 Adverse Events for Bariatric Endoscopic Procedures as Compared to Lifestyle or Surgery

Study, Year; Design | Total Complication | 30-day Readmission | 30-day Reintervention | Nausea | Vomiting | Dehydration | Abdominal Pain | Gastric Ulceration | Bleeding | GERD
IGB vs Lifestyle
Moore 2019; Case series | 14.3% | | | 63% | 31% | 0.07% | 5.29% | 0.82% | | 0.82%
Sander 2017; Case series | | | | | | | | | 0.01%
Mathus-Vliegen 2015; Case series | 5.9% | | 0.2% | | | 0.2% | | 0.9% | 0.6%
Sullivan 2018; RCT | Risk Diff (CI); 0.25 (0.17, 0.32) | | | 0.38 (0.29, 0.46) | 0.07 (0.01, 0.14) | −0.01 (−0.02, 0.01) | 0.49 (0.41, 0.58) | 0.01 (0, 0.01) | 0.06 (0.03, 0.09)
Courcoulos 2017; RCT | 0.27 (0.19, 0.35) | 7.5 | | 0.82 (0.75, 0.88) | 0.70 (0.62, 0.78) | 0.14 (0.09, 0.2) | 0.54 (0.45, 0.62) | | | 0.25 (0.17, 0.33)
Abu Dayyeh 2021; RCT | 0.03 (0, 0.06) | | 0.00 (0, 0) | 0.90 (0.86, 0.95) | 0.71 (0.65, 0.78) | 0.02 (0, 0.04) | 0.56 (0.49, 0.63) | 0.02 (0, 0.04)
Ponce 2012; RCT | 0.33 (0.13, 0.53)
Pone 2015; RCT | 0.57 (0.5, 0.64) | | | | | | | 0.35 (0.28, 0.42)
Fuller 2013; RCT | | | | 0.72 (0.55, 0.89) | 0.69 (0.51, 0.86) | 0.26 (0.1, 0.41) | 0.56 (0.37, 0.74)
ESG vs Lifestyle
Alqahtani 2019; Case series | | 2.4% | | 92.4% | | | | | 0.7%
Sullivan 2017; RCT | 0.09 (0.01, 0.17) | | | 0.14 (0.07, 0.21) | 0.19 (0.13, 0.24) | | | | 0.01 (0, 0.01) | 0.04 (−0.02, 0.09)
Cheskin 2020; Observ. | 0.05 (0.01, 0.09) | | | | | 0.01 (−0.01, 0.03) | | 0.03 (0, 0.06)
AspireAssist vs Lifestyle
Thompson 2017; RCT | 0.78 (0.71, 0.86) | | 0.01 (−0.01, 0.03) | | 0.17 (0.1, 0.24) | | 0.38 (0.29, 0.47) | | 0.02 (−0.01, 0.04)
ESG vs LSG
Fayad 2019; Observ. | −0.12 (−0.23, 0) | −0.06 (−0.18, 0.07) | 0.00 (0, 0) | | 0.01 (0.01, 0.16) | −0.01 (−0.04, 0.01) | | | −0.03 (−0.07, 0.01) | −0.13 (−0.22, −0.03)
Fiorillo 2020; Observ. | −0.04 (−0.13, 0.04) | −0.04 (−0.13, 0.04) | | | | | | | −0.04 (−0.13, 0.04) | −0.30 (−0.49, −0.12)
Lopez-Nava 2021; Observ. | −0.04 (−0.1, 0.01) | | | | | | | | −0.04 (−0.1, 0.01)
Novikov 2018; Observ. | −0.07 (−0.13, −0.01) | −0.02 (−0.04, 0.01) | −0.04 (−0.09, −0.01) | | −0.01 (−0.02, 0.01)

Note. Data are presented as mean difference between comparative arms when appropriate, where positive values favor endoscopic therapy and negative values favor comparative arm. For case series, complication data are presented in percentages.

Abbreviations. ESG=endoscopic sleeve gastroplasty; IGB=intragastric balloon; LSG=laparoscopic sleeve gastrectomy.

## KEY QUESTION 3 Do the comparative effectiveness and/or harms vary by patient or intervention characteristics (ie, age, BMI, type intragastric balloon, gastroplasty technique, etc)?

Study designs and procedures varied considerably, making the ability to compare effectiveness and harm of interventions based on patient characteristics or procedural technique limited. For all the studies included in this review, factors such as baseline age or BMI were not variables that were prospectively assessed or reported in terms of their association with clinical outcomes.

### Intragastric Balloon

There were 7 RCTs with detailed demographic and pre-procedural data available for review. Four studies examined the Orbera intragastric balloon^13,20,38,54^ and 1 the Obalon IGB^55^ against lifestyle modification. Two studies investigated the Reshape dual intragastric balloon.^26,28^ One study investigated the Spatz adjustable balloon.^26^ There was no direct comparison between the Orbera and Obalon; therefore, conclusions about which type of IGB is more effective based on these 3 trials are limited.

We identified 1 small comparative study looking at the BioEnterics Intragastric Balloon against the Spatz Adjustable Balloon.^56^ This single center experience of 20 patients showed equivocal differences in weight loss at 6 months (20kg for both) and adverse events rate. However, given the small sample size, no conclusions can be drawn. Two small observational studies assessed the effects of IGB on liver stiffness, function, and fibrosis in patients with nonalcoholic fatty liver disease (NAFLD), finding significant improvements in liver abnormalities in patients with this condition who undergo IGB placement.^57,58^

### Endoscopic Sleeve Gastroplasty

There were multiple cohort studies comparing ESG to LSG.^32–34,36,37^ Across all studies, the mean age was similar, ranging from 40-48 years. There were notable differences in baseline characteristics for 3 studies.^32,34,36^ In the study by Novikov et al,^32^ LSG patients had baseline higher BMIs (47.2 vs 38.6, respectively) and a higher percentage of patients had diabetes (20.5% vs 3.7%) compared to ESG patients. In 3 observational studies,^32,34,36^ LSG patients also had significantly higher rates of hypertension. These studies demonstrate that patients with higher BMI with or without metabolic syndrome are more likely to get bariatric surgery overall, but no conclusion can be drawn regarding whether higher BMI or metabolic syndrome affects percent weight loss.

### Aspiration Therapy

There are 2 RCTs evaluating AspireAssist to lifestyle with no significant baseline differences.^39,41^

High-quality randomized trials are necessary to assess these key questions in order to optimize patient selection for various bariatric therapies.

## CERTAINTY OF EVIDENCE

Our assessments of the certainty of evidence, using the GRADE Framework, are presented in Table 3. In making these determinations, we factored in our assessments of risk of bias for the studies when judging the degree of study limitations. We considered all the studies to satisfy the directness domain, as all studies measured weight loss, QOL, a metabolic outcome, or complications in standard ways. We considered the consistency and precision domains in the context of the conclusion about each outcome. As an example, for the conclusion that %TBWL is greater in patients treated with an IGB than with lifestyle therapy, we considered the results across studies as consistent and precise if they all had the same finding – that weight loss was significantly greater in patients treated with intragastric balloon therapy – even if the studies found values of %TBWL favoring balloon therapy between 4% and 12%. We did this because we judged the practice-relevant decision was “will this therapy result in greater weight loss?” and not on the precise amount of weight loss. Also, in studies where the comparison was lifestyle therapy, we drew on the large body of literature about lifestyle therapy for weight loss to conclude that complications like reintervention, bleeding, and gastric ulceration can safely be assumed to be negligible, such that the presence of any of these in the intervention groups receiving balloon therapy, gastric sleeve therapy, etc, can be more strongly attributed to the intervention. Likewise, the limited effectiveness of lifestyle therapies to yield sustained weight loss increases our certainty that statistically significant benefits favoring an interventional therapy are likely to be causal.

We judged 7 conclusions as being high certainty of evidence, and all were in comparisons between endoscopic interventions and lifestyle therapies: 1) IGB achieves greater %TBWL than lifestyle therapy at 6 and 12 months; 2) IGB achieves more %EBWL than lifestyle therapy at 6 months; 3) ESG achieves more %TBWL than lifestyle therapy at 6 months; and 4) AspireAssist, IGB, and ESG each have greater total complications than lifestyle therapy.

Table 3 GRADE Certainty of Evidence

Outcome | Study Limitations | Consistency | Directness | Precision | Certainty of Evidence
%TBWL
At 6 months
IBG > Lifestyle | RCT: No serious limitations; Unmatched observational studies: Serious | Consistent | Direct | Precise | High
ESG > Lifestyle | Matched observational studies: Serious; Unmatched observational studies: Serious | Consistent | Direct | Imprecise | Low
ESG < LSG | Matched observational studies: Serious; Unmatched observational studies: Serious | Consistent | Direct | Precise | Low
At 12 months
AspireAssist > Lifestyle | RCT: No serious limitations | N/A | Direct | Precise | Moderate
AspireAssist < RYGB | Unmatched observational studies: Serious limitations | N/A | Direct | Precise | Low
IGB > Lifestyle | RCT: No serious limitations; Unmatched observational studies: Serious limitations | Consistent | Direct | Precise | High
ESG > Lifestyle | RCT: No serious limitations | Consistent | Direct | Precise | High
ESG < LSG | Unmatched observational studies: Serious limitations | Consistent | Direct | Precise | Low
%EBWL
At 6 months
IGB > Lifestyle | RCT: No serious limitations | Consistent | Direct | Precise | High
ESG > Lifestyle | RCT: No serious limitations | N/A | Direct | Precise | Moderate
ESG < LSG | Matched observational studies: Serious limitations | N/A | Direct | Precise | Low
At 12 months
AspireAssist > Lifestyle | RCT: No serious limitations | N/A | Direct | Precise | Moderate
AspireAssist < RYGB | Unmatched observational studies: Serious limitations | N/A | Direct | Precise | Low
IGB > Lifestyle | RCT: No serious limitations | N/A | Direct | Precise | Moderate
ESG > Lifestyle | RCT: No serious limitations | N/A | Direct | Precise | Moderate
HbA1C
At 6 months
IGB = Lifestyle | RCT: No serious limitations | N/A | Direct | Precise | Moderate
ESG = Lifestyle | RCT: No serious limitations | N/A | Direct | Precise | Moderate
AspireAssist = Lifestyle | RCT: Very serious limitations | N/A | Direct | N/A | Very low
Quality of Life
At 12 months
ESG > Lifestyle | RCT: No serious limitations | N/A | Direct | Precise | Low
ESG = LSG | Unmatched observational studies: Serious limitations | N/A | Direct | Imprecise | Very Low
Total Complications
At 6 months
AspireAssist > Lifestyle | RCT: No serious limitations | N/A | Direct | Precise | High
IGB > Lifestyle | RCT: No serious limitations | Consistent | Direct | Precise | High
ESG > Lifestyle | RCT: No serious limitations | Consistent | Direct | Precise | High
ESG = LSG | Matched observational studies: Serious limitations; Unmatched observational studies: Serious limitations | Consistent | Direct | Precise | Low

Abbreviations. ESG=endoscopic sleeve gastroplasty; IGB=intragastric balloon; LSG=laparoscopic sleeve gastrectomy; RYGB=Roux-en-Y gastric bypass.