# METHODS

## TOPIC DEVELOPMENT

This topic was developed in response to a nomination by Jason A. Dominitz, MD, MHS National Program Director, National Gastroenterology and Hepatology Program Office, Veterans Health Administration. Key questions were then developed with input from the topic nominator, the ESP Coordinating Center, the review team, and a technical expert panel (TEP).

## KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ1 What is the comparative effectiveness of endoscopic bariatric interventions versus lifestyle interventions or bariatric surgery?
KQ2 What are the comparative harms of endoscopic bariatric interventions versus lifestyle interventions or bariatric surgery?
KQ3 Do the comparative effectiveness and/or harms vary by patient or intervention characteristics (ie, age, BMI, type of procedure [intragastric balloon, endoscopic gastric reduction, etc])?

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42021270205).

## DATA SOURCES AND SEARCHES

We conducted broad searches using terms relating to “gastric balloon” or “bariatric surgical procedure” or “endoscopic gastroplasty.” We searched PubMed (1/1/2014-12/7/2021), Embase (1/1/2014-12/7/2021), and Cochrane (1/1/2014-12/7/2021). A search focusing on “endoscopic bariatric therapy” was conducted January 23, 2022, and utilized the same databases and search parameters as the initial search. We limited the search to 2014 onwards, as these therapies were being approved by FDA in 2015-2017. Studies published prior to 2014 would have been based on data from procedures done in 2012 or earlier, and we did not consider evidence from this period to be relevant to current practice. See Appendix A for complete search strategy.

## STUDY SELECTION

Two team members working independently screened the titles of retrieved citations. For titles deemed relevant by at least 1 person, abstracts were then screened independently in duplicate by 2 team members. All disagreements were reconciled through group discussion. Full-text review was conducted in duplicate by 2 independent team members with any disagreements resolved through discussion. Studies were included at either the abstract or the full-text level if they were RCTs or observational studies comparing a bariatric endoscopic procedure to alternate bariatric therapies (pharmaceutical, endoscopic, or surgical) or lifestyle management. Studies with fewer than 10 participants were excluded during screening.

We included all RCTs regardless of outcomes studied or sample size. Observational studies were subjected to additional selection criteria. Studies with a comparative arm (regardless of sample size) were included. All cases series (eg, studies with no comparison treatment arm) were excluded, regardless of sample size, for analysis of the primary outcomes; however, case series with greater than 500 participants were included for complication outcomes. Additionally, observational studies from the same data source, either large databases or single institutional databases, were considered to have a large overlap if >50% of the same subjects were included in multiple publications or if there was >50% overlap in the enrollment period. In this instance, the publication with the most recent data and the most outcomes of interest was included.

We excluded studies where the bariatric procedure was used solely as a bridge to weight loss prior to bariatric surgery, as this fell outside the scope of interest of VA stakeholders. We also excluded studies where similar endoscopic mechanisms were compared to each other (eg, IGB vs IGB, primary obesity surgery endoluminal vs endoscopic sleeve gastroplasty, etc), as well as those that compared adjustments of endoscopic bariatric therapies in unapproved ways (eg, variable balloon inflation volume, number of intragastric balloons, etc) or investigational procedures (ie, duodenal-jejunal bypass liner, Endomina, botulinum injection, duodenal mucosal resurfacing).

## DATA ABSTRACTION AND ASSESSMENT

Data extraction was completed in duplicate. All discrepancies were resolved with full group discussion. We abstracted data on study design, sample size, perioperative outcomes (weight loss, reoperations/revisions, 30-day readmissions, adverse events, effects on obesity-related comorbid conditions, mortality) and some outcomes that were procedure specific (IGB-related complications such as premature removal due to intolerance, fistula or gastric ulceration; AspireAssist-related stomal irritation, etc). We also abstracted data needed for the Cochrane Risk of Bias tool or Cochrane Risk of Bias In Non-randomized Studies – of Interventions (ROBINS-I). We looked for outcomes for weight loss at 6 months, 12 months, 24 months, 36 months, 48 months, and last follow-up if longer than 48 months, or the time closest to these follow-up periods.

RCTs were assessed for quality (risk of bias) with the Cochrane Risk of Bias tool. This tool requires an assessment of whether a study is at high or low (or unknown) risk of bias in 7 domains: random sequence generation, allocation concealment, blinding of participants and personnel, blinding of outcome assessment, incomplete outcome data, selective outcome reporting, and other (see Appendix C for tool; Appendix E for table). We used ROBINS-I for observational studies. This tool requires an assessment of whether a study is at critical, serious, moderate, or low risk of bias (or no information) in 7 domains: confounding, selection bias, bias in measurement classification of interventions, bias due to deviations from intended interventions, bias due to missing data, bias in measurement of outcomes, and bias in selection of the reported result (see Appendix D for tool; Appendix F for table). Since observational studies are not required to have published an a priori protocol, we operationalized the last domain (bias in selection of the reported result) as requiring that studies report the most common variables.

We used the criteria of the Grading of Recommendations Assessment, Development and Evaluation (GRADE) working group.^19^ GRADE assesses the certainty of the evidence based on the assessment of the following domains: risk of bias, imprecision, inconsistency, indirectness, and publication bias. This results in categories as follows:

- High: We are very confident that the true effect lies close to that of the estimate of the effect.
- Moderate: We are moderately confident in the effect estimate. The true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.
- Low: Our confidence in the effect estimate is limited. The true effect may be substantially different from the estimate of the effect.
- Very low/Insufficient: We have very little confidence in the effect estimate. The true effect is likely to be substantially different from the estimate of effect.

## SYNTHESIS

### Pooled Data

For comparisons with at least 3 studies of the same intervention and similar patient populations and the same outcome, we performed random-effects meta-analyses. We conducted a meta-analysis of 6-month weight loss outcomes (%TBWL and mean percent excess body weight loss [%EBWL]) for RCTs and observational studies of IGB versus lifestyle, and for observational studies of ESG versus LSG. Pooled estimates of effect are reported as mean difference (MD) with their 95% confidence intervals (CI). Random-effects meta-analyses were conducted using the Hartung-Knapp-Sidik-Jonkman method. The presence of publication bias was evaluated using Begg rank correlation^17^ and Egger regression tests.^18^ p-values < .05 were considered statistically significant.

### Non-pooled Data

A narrative analysis was performed for the remainder of our outcomes. Continuous outcomes were analyzed using the mean or median along with a measure of dispersion (standard deviation, inter-quartile range) to calculate the difference and 95% CI between arms. For binary outcomes, the number of subjects with the outcome was collected and a risk difference was derived with its 95% CI.

We created figures for adverse events with 3 or more studies and included all in Appendix H. Graphical representations of the outcomes’ risk and mean differences and 95% CI were plotted when available or estimable using counts and sample sizes. We noted where significance differed between the study-reported p-value and calculated risk or mean differences and 95% CI. For rare outcome events, risk differences were preferentially used during analysis.

All analyses were carried out with the metafor package in R version 4.0.2 (R Foundation for Statistical Computing, Vienna, Austria).