# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) developed the present report in response to a request from the Veterans Health Administration (VHA) National Gastroenterology and Hepatology Program Office.

## BACKGROUND

The growing prevalence of obesity worldwide is notable. According to a 2016 study by the World Health Organization (WHO), over 1.9 billion adults are considered overweight and another 500 million adults are obese.^1^ Obesity contributes to a range of harmful comorbidities spanning cardiovascular disease, type 2 diabetes, cancer, osteoarthritis, non-alcoholic fatty liver disease, and sleep apnea.^2,3^ The economic burden on the United States healthcare system, when including direct and indirect costs, approximates $150 billion dollars per year.^4^ Targeted pharmacologic, endoscopic, and surgical therapies have been developed in the effort to expand therapeutic options for treating obesity.

Bariatric surgery remains a gold-standard treatment of morbid obesity and is effective at reducing weight, along with obesity-related conditions, which translates into improved long-term survival.^5^ The American Society of Metabolic and Bariatric Surgery (ASMBS) estimates that in 2019, laparoscopic sleeve gastrectomy (LSG) represented 60% of all bariatric procedures performed domestically, with Roux-en-Y gastric bypass (RYGB) encompassing 18%, and adjustable gastric band (AGB) and duodenal switch each constituting only 0.9%. The only endoscopic bariatric therapy tracked by ASMBS, intragastric balloon (IGB), comprised 1.8% of total bariatric procedures.^6^ There is strong evidence from observational studies and randomized controlled trials (RCTs) that bariatric surgery is an effective intervention for substantial and durable weight loss. Long-term studies with 10-year follow-up have demonstrated mean percent excess weight loss of 60% following RYGB, 49% following AGB, and 57% following LSG in certain populations.^7^ Though rare, surgery is associated with a risk of severe morbidity and mortality for an elective operation, approximately 4% and 0.1%, respectively. Additionally, most of these operations are not easily reversible.^8^

Despite the prevalence of obesity and the proven efficacy of surgery, few who qualify ultimately receive this intervention.^9^ It is estimated that 256,000 bariatric surgeries were performed in 2019, which accounts for less than 1% of American patients eligible based on BMI.^6^ This gap is even more pronounced in the VA population. According to the 2014 VA/Department of Defense obesity guideline summary, 78% of Veterans are overweight or obese resulting in an annual cost of $370 per patient due to medical- or non-medical-related care.^10^ The VA performs approximately 500 bariatric surgeries annually across 17-21 centers. Comprehensive and interdisciplinary management thus far has focused on lifestyle modification and medications through programs like MOVE! (MOVE! Weight Management Program) or referral to bariatric surgery. However, given the large percentage of Veterans who are obese receiving care through the VA and the strong association of obesity with comorbid conditions, detailed evaluation of less-invasive therapeutic options is requested by VA stakeholders.

There remains a treatment gap for patients who experience limited weight loss with conservative therapies (eg, lifestyle modification, medications), and at the same time, do not qualify for or otherwise do not have access to surgery, or are reluctant because of the potential operative risks. Endoscopic bariatric therapy is a viable alternative to traditional therapies.^11^ Over the past 10 years, various endoscopic modalities have been developed that focus on either primary gastric (IGB, endoscopic sleeve gastroplasty [ESG], aspiration therapy) or small bowel (luminal liners, resurfacing or shuttles) interventions. Preliminary studies have shown promising results, including mean percent total body weight loss (%TBWL) of 18-20% 1 year following ESG^1,12^ and 8-12% following IGB.^13,14^ Endoscopic therapies came to market quickly, as compared to their surgical counterparts, and questions remain about their efficacy and safety. Additionally, the differences in efficacy between therapies are not well described, which may lead practitioners to be uncertain about recommending them to patients who may qualify.

Systematic reviews comparing endoscopic bariatric therapies to surgical intervention, lifestyle intervention, and other endoscopic treatments have methodological variations and inconsistent reporting of obesity and metabolic syndrome-related outcomes.^14–16^ This is complicated further by the wide variety of existing therapies available, as well additional novel therapies that are being considered for US Food and Drug Administration (FDA) approval in the near future. Endoscopic bariatric interventions are increasingly being utilized for a broad population of patients with morbid obesity, and it is imperative to examine how they compare to surgical and lifestyle therapies. We conducted a systematic review to help clinicians, patients, and policymakers understand these new approaches in comparison to traditional bariatric surgery. In this review, we aim to assess the impact of endoscopic bariatric therapies on weight loss, morbidity, mortality, and resolution of comorbid conditions.