# APPENDIX I CITATIONS FOR EXCLUDED PUBLICATIONS

## Adjunct Therapies, N = 8

1 Badurdeen, D., ., Endoscopic sleeve gastroplasty plus liraglutide versus endoscopic sleeve gastroplasty alone for weight loss. Gastrointestinal endoscopy, 2021. 93(6): p. 1316–1324.e1.33075366
2 Badurdeen, D., ., ESG PLUS LIRAGLUTIDE IS SUPERIOR TO ESG ALONE FOR WEIGHT LOSS IN OVERWEIGHT AND OBESE PATIENTS. Gastrointestinal Endoscopy, 2020. 91(6): p. AB215.
3 Carolina Hoff, A., ., SEMAGLUTIDE IN ASSOCIATION TO ENDOSCOPIC SLEEVE GASTROPLASTY: TAKING ENDOSCOPIC BATRIATRIC PROCEDURES OUTCOMES TO THE NEXT LEVEL. Gastrointestinal Endoscopy, 2021. 93(6): p. AB6–AB7.
4 de Souza, T.F., ., The First Study Evaluating Effectiveness and Safety of the Endoscopic Sleeve Gastroplasty in HIV Patients. Obesity surgery, 2020. 30(3): p. 1159–1162.31933107
5 Hoff, A.C., ., Endoscopic sleeve gastroplasty and liraglutide: Associating a GLP1-analogue to potentialize weight loss. Digestive Endoscopy, 2020. 32((Hoff A.C.) Angioskope SP, Bariatric Endoscopy, São Paulo, Brazil): p. 14.
6 Kolli, S., ., THE DUAL EFFICACY OF PHARMACOTHERAPY WITH INTRAGASTRIC BALLOONS FOR SUSTAINED WEIGHT LOSS – A RETROSPECTIVE ANALYSIS. Gastrointestinal Endoscopy, 2020. 91(6): p. AB227.
7 Peker, Y., ., Comparison of results of laparoscopic gastric banding and consecutive intragastric balloon application at 18 months: a clinical prospective study. Journal of laparoendoscopic & advanced surgical techniques. Part a, 2011. 21(6): p. 471–475.21612448
8 Russo, T., ., BioEnterics Intragastric Balloon (BIB) versus Spatz Adjustable Balloon System (ABS): Our experience in the elderly. International journal of surgery (London, England), 2017. 38: p. 138–140.27353844

## Bridging Therapy, N = 1

1 Rzepa, A., . (2019). “Selected aspects of intra-gastric balloons use in patients undergoing surgery for morbid obesity.” Obesity surgery 29(5): 551.

## Duplicate Data, N = 3

1 Fuller, N., ., A prospective, randomised, controlled trial of the BioEnterics® Intragastric Balloon (BIB) in the treatment of obese individuals with metabolic syndrome. Obesity reviews, 2010. 11: p. 436-.
2 Fuller, N.R., ., An intragastric balloon produces large weight losses in the absence of a change in ghrelin or peptide YY. Clinical obesity, 2013. 3(6): p. 172–179.25586733
3 Klein, S., ., Aspiration therapy: a novel endoscopic approach for treating obesity. Obesity facts., 2012. 5: p. 203.

## Modified Procedures, N = 7

1 Alasfar, F.S. and F. Alotaibi, A comparison between swallowable fluid filled and air filled gastric balloon: A single surgeon experience. Surgical Endoscopy, 2019. 33((Alasfar F.S.; Alotaibi F.) Department of Surgery, Faculty of Medicine, Kuwait University): p. S35.
2 Barrichello, S.A., ., ANALYSIS OF THE EFFICACY AND SYMPTOMATOLOGY OF THE BALLOON IN RELATION TO THE VOLUME OF THE ACCESSORY. “INTRAGASTRIC BALLOON - THE GREATER THE VOLUME, THE BETTER?”. Gastrointestinal Endoscopy, 2019. 89(6): p. AB274–AB275.
3 Fittipaldi-Fernandez, R.J., ., Randomized Prospective Clinical Study of Spatz3® Adjustable Intragastric Balloon Treatment with a Control Group: a Large-Scale Brazilian Experiment. Obesity surgery, 2021. 31(2): p. 787–796.33001381
4 Folini, L., ., Liver steatosis (LS) evaluated through chemical-shift magnetic resonance imaging liver enzymes in morbid obesity; effect of weight loss obtained with intragastric balloon gastric banding. Acta diabetologica, 2014. 51(3): p. 361–368.24085682
5 Malik, S., ., INTRA-GASTRIC BALLOON FOR TREATMENT OF OBESITY: SAFETY ANALYSIS OF 2407 PATIENTS PERFORMED BY GASTROENTEROLOGISTS AND SURGEONS. Gastrointestinal Endoscopy, 2019. 89(6): p. AB271–AB272.
6 Mosli, M.M. and M. Elyas, Does combining liraglutide with intragastric balloon insertion improve sustained weight reduction? Saudi journal of gastroenterology : official journal of the Saudi Gastroenterology Association, 2017. 23(2): p. 117–122.28361843
7 Sadek, R. and A. Wassef, Comparative gastric balloon systems: Does size matter? endoscopic and percutaneous interventional procedures. Obesity Surgery, 2017. 27(1): p. 345.

## No Data, N = 4

1 Nct, Efficacy and Safety of Endoscopic Sleeve Gastroplasty Versus Laparoscopic Sleeve Gastrectomy in Obese Subjects With NASH. https://clinicaltrials.gov/show/NCT04060368, 2019.
2 Pate, P., ., Impact of combined medical weight loss and intra-gastric balloon therapy on body fat composition following completion of 6 months of treatment punam patel md, michael seger md, jennifer seger md, terive duperier md, richard englehardt md, allison arnett NP-BC, tamara deshazo np. Surgery for obesity and related diseases, 2017. 13(10): p. S198–S199.
3 Plua Marcillo, W., ., Prospective analysis of results of laparoscopic gastric sleeve and intragastric ball in obese patients. Obesity Surgery, 2019. 29(5): p. 1112.
4 Solmaz, A., ., Comparison of intragastric balloon and gastric plication. Obesity Surgery, 2015. 25(1): p. S262.

## Non-Bariatric Outcomes, N = 5

1 Abu Dayyeh, B.K., ., Baseline gastric emptying and its change in response to diverse endoscopic bariatric therapies predict weight change after intervention. Gastroenterology, 2016. 150(4): p. S86.
2 Fayad, L., ., ENDOSCOPIC BARIATRIC THERAPIES ASSOCIATED WITH LOWER RATE OF ADVERSE EVENTS AND LENGTH OF STAY THAN LAPAROSCOPIC BARIATRIC THERAPIES. Gastrointestinal Endoscopy, 2020. 91(6): p. AB223–AB224.
3 Goff, J.L., Gastroplasty with stomach plication gp associated with significant psychological support: A real alternative to the sleeve and gastric by-pass. Obesity Surgery, 2014. 24(8): p. 1245–1246.
4 Kolesnikov, E., ., Comperative ph-monitoring studies after Roux-en-Y gastric bypass, sleeve gastrectomy operations and intragastric balloon insertion in morbidly obese patients. Obesity Surgery, 2015. 25(1): p. S274.
5 Wroblewski, E., ., Variation in blood levels of hormones in obese patients following weight reduction induced by endoscopic and surgical bariatric therapies. Cytokine, 2016. 77: p. 56–62.26539806

## Procedure Type Not Included, N = 10

1 Cruz, J., . (2017). “Efficacy of weight reduction of endoscopic intrasgastric balloon (IGB) vs oral sibutramine in patients with class i obesity in an asian cohort-a randomized control trial with long term follow up. Surgery and strategies for low BMI.” Obesity surgery 27(1): 235-.
2 Durmus, A., ., The Efficacy Of Intragastric Balloon Versus Botulinum Toxin Injection In Obese Patients. Surgery for Obesity and Related Diseases, 2019. 15(10): p. S187–S188.
3 Familiari, P., ., Transoral gastroplasty for morbid obesity: a multicenter trial with a 1-year outcome. Gastrointestinal endoscopy, 2011. 74(6): p. 1248–1258.22136774
4 Huberty, V., ., Endoscopic sutured gastroplasty in addition to lifestyle modification: short-term efficacy in a controlled randomised trial. Gut, 2020.
5 Jonnalagadda, S.S., ., Preliminary results of a randomized, blinded, sham-controlled trial of transoral gastroplasty for the treatment of morbid obesity. Gastroenterology, 2012. 142(5): p. S78-.
6 Lecumberri, E., ., Effectiveness and safety of air-filled balloon heliosphere BAG in 82 consecutive obese patients. Obesity surgery, 2011. 21(10): p. 1508–1512.21221835
7 Nanni, G., ., Effectiveness of the transoral endoscopic vertical gastroplasty (TOGa): a good balance between weight loss and complications, if compared with gastric bypass and biliopancreatic diversion. Obesity surgery, 2012. 22(12): p. 1897–1902.23001571
8 Popov, V., A. Ou, and C.C. Thompson, Intragastric balloons are effective at inducing weight loss: a systematic review and meta-analysis of randomized controlled trials. Gastroenterology, 2015. 148(4): p. S903-.
9 Rothstein, R.I., ., TRANSPYLORIC SHUTTLE TREATMENT IMPROVES CARDIOMETABOLIC RISK FACTORS AND QUALITY OF LIFE IN PATIENTS WITH OBESITY: RESULTS FROM A RANDOMIZED, DOUBLE-BLIND, SHAM-CONTROLLED TRIAL. Gastroenterology, 2019. 156(6): p. S-237-.
10 Schouten, R., ., Long-term results of bariatric restrictive procedures: a prospective study. Obesity surgery, 2010. 20(12): p. 1617–1626.20563663

## Sample Size, N = 6

1 IMPACT OF SINGLE FLUID-FILLED INTRAGASTRIC BALLOON ON METABOLIC PARAMETERS AND NONALCOHOLIC STEATOHEPATITIS: a PROSPECTIVE PAIRED ENDOSCOPIC ULTRASOUND GUIDED CORE LIVER BIOPSY AT THE TIME OF BALLOON PLACEMENT AND REMOVAL. Gastroenterology, 2018. 154(6): p. S-1360-.
2 Genco, A., ., Safety and efficacy of a new swallowable intragastric ballon not needing endoscopy: earlyitalian experience. Gastrointestinal endoscopy, 2017. 85(5): p. AB271-.
3 Jagtap, N., ., Endoscopic sleeve gastroplasty for non-alcoholic fatty liver disease. Endoscopy, 2021. 53(SUPPL 1): p. S21-.
4 Lopez-Nava, G., ., Endoscopic Sleeve Gastroplasty for Obesity: a Multicenter Study of 248 Patients with 24 Months Follow-Up. Obesity surgery, 2017: p. 1–7.
5 Machytka, E., ., Elipse, the first procedure less gastric balloon for weight loss: a prospective, observational, open-label, multicenter study. Endoscopy, 2016. (no pagination).
6 Maekawa, S., M. Niizawa, and M. Harada, A Comparison of the Weight Loss Effect between a Low-carbohydrate Diet and a Calorie-restricted Diet in Combination with Intragastric Balloon Therapy. Internal medicine (Tokyo, Japan), 2020. 59(9): p. 1133–1139.32378654

## Short Follow-Up, N = 4

1 Armijo, P.R., ., Patients undergoing intra-gastric balloon achieve approximately 50% of their target weight loss in the first month postoperatively: a Metabolic and Bariatric Surgery Accreditation and Quality Improvement Program analysis. Surgery for Obesity and Related Diseases, 2018. 14(11): p. S63.
2 Armijo, P.R., ., Patients undergoing intragastric balloon achieve approximately 50% of their target weight loss in the first month postoperatively: an MBSAQIP analysis. Surgery for obesity and related diseases : official journal of the American Society for Bariatric Surgery, 2019. 15(12): p. 2060–2065.31668944
3 Behzadi, F., ., Predictors of Early Reintervention Following Intragastric Balloon: An MBSAQIP Analysis. Surgery for Obesity and Related Diseases, 2019. 15(10): p. S74.
4 Jain, S., S. Rajput, and R.K. Jain, Endoscopic Sleeve gastroplasty is safe minimally invasive modality in treatment of obesity with good short term efficacy: Initial experience at single center. Journal of Gastroenterology and Hepatology, 2019. 34((Jain S.; Jain R.K.) Jainamshree Multispecialty Hospital, Bhopal, India): p. 454.

## Study Design, N = 19

1 Abeid, M., ., EFFICACY AND SAFETY OF INTRAGASTRIC BALLOON PLACEMENTS IN 1600 CASE, AN EXPERIENCE FROM THE MIDDLE EAST. Gastrointestinal Endoscopy, 2019. 89(6): p. AB263.
2 Deliopoulou, K., ., The impact of weight loss on depression status in obese individuals subjected to intragastric balloon treatment. Obesity surgery, 2013. 23(5): p. 669–675.23299506
3 Fayad, L., ., Endoscopic sleeve gastroplasty versus intragastric balloon insertion: efficacy, durability, and safety. Endoscopy, 2019. 51(6): p. 532–539.30841009
4 Fernandez, R.J.F., ., Intragastric balloon: A critical view in non elective bariatric surgery patients. United European Gastroenterology Journal, 2017. 5(5): p. A830.
5 Fittipaldi-Fernandez, R., ., Intragastric balloon: A critical view in non elective bariatric surgery patients endoscopic and percutaneous interventional procedures. Obesity Surgery, 2017. 27(1): p. 494–495.
6 Ienca, R., C. Giardiello, and R. Schiano, Virtual follow-up (FU) program enhances weight-loss results post Elipse balloon: an innovative, digital patient-friendly approach. Obesity facts, 2018. 11: p. 49-.
7 Ienca, R., ., Elipse® swallowable intragastric balloon + very low calorie ketogenic diet (VLCKD): a novel strategy to optimize weight-loss and minimize side effects. Obesity surgery, 2018. 28(1): p. S49–S50.
8 Jaruvongvanich, V., ., CHALLENGES AND SUCCESS OF INTRAGASTRIC BALLOON THERAPY IN LIVER TRANSPLANT CANDIDATES: A PROSPECTIVE STUDY WITH LONG-TERM FOLLOW-UP. Gastrointestinal Endoscopy, 2020. 91(6): p. AB211–AB212.
9 Lopez-Nava, G., ., EUROPEAN ENDOSCOPIC SUTURING REGISTRY FOR TREATMENT OF OBESITY. Gastrointestinal Endoscopy, 2020. 91(6): p. AB62.
10 Ohta, H., CAN INTRAGASTRIC BALLOON THERAPY NORMALIZE THE GUT DYSBIOSIS OF PATIENTS WITH OBESITY? Gastroenterology, 2019. 156(6): p. S-678.
11 Popov, V., ., The impact of intragastric balloons on metabolic disease in veterans: Results of a 6-month pilot study. Gastroenterology, 2017. 152(5): p. S639.
12 Sander, B., ., Brazilian multicenter study of endoscopic sleeve gastroplasty with over stitch use-initial results. United european gastroenterology journal, 2019. 7(8): p. 744-.
13 Storm, A.C. and B.K. Abu Dayyeh, Endoscopic sleeve gastroplasty for obesity: defining the risk and reward after more than 1600 procedures. Gastrointestinal endoscopy, 2019. 89(6): p. 1139–1140.31104746
14 Storm, A.C. and B.K. Abu Dayyeh, Metabolic function and weight loss after endoscopic sleeve gastroplasty: resistance is futile. Gastrointestinal endoscopy, 2021. 93(5): p. 1119–1120.33691979
15 Suchartlikitwong, S., ., Intragastric balloons in severe obesity: A new capability. Gastrointestinal Endoscopy, 2018. 87(6): p. AB605.
16 Sullivan, S. and S. Edmundowicz, Early Experience With Endoscopic Sleeve Gastroplasty and Hints at Mechanisms of Action. Clinical gastroenterology and hepatology : the official clinical practice journal of the American Gastroenterological Association, 2017. 15(1): p. 44–45.27693522
17 Vargas, E.J., ., Effectiveness of Online Aftercare Programs Following Intragastric Balloon Placement for Obesity Is Similar to Traditional Follow-up: a Large Propensity Matched US Multicenter Study. Obesity surgery, 2019. 29(12): p. 4036–4042.31346983
18 Wallstabe, I., ., Endoscopic sleeve gastroplasty using the novel Endomina device for morbidly obese patients. 2018: Germany.
19 Wannhoff, A., ., Endoscopic sleeve gastroplasty for severe obesity by full-thickness suturing using the GERDX device. 2019: Germany.

## Unavailable, N = 11

1 Buzga, M., ., Effect of endoscopic gastroplasty and surgical plication of the stomach on bodycomposition: Short term, 6 months study. Vnitrni Lekarstvi, 2017. 63(9): p. 2S47–2S48.
2 Dayyeh, B.A., ., Laparoscopic greater curvature plication (LGCP) VS. Endoscopic Sleeve Gastroplasty (ESG): Similar efficacy with different physiology. Surgery for Obesity and Related Diseases, 2017. 13(10): p. S205.
3 Hollenbach, M., ., Pre-Study protocol Weight-loss Endoscopy Trial (WET): A multicenter, randomized, controlled trial comparing weight loss in endoscopically implanted duodenal-jejunal bypass liners vs. intragastric balloons vs. a sham procedure. Zeitschrift fur Gastroenterologie, 2017. 55(8).
4 Kadouh, H., ., Pharmacotherapy enhances weight loss maintenance after obesity treatment with the intragastric balloon. Surgery for Obesity and Related Diseases, 2017. 13(10): p. S209.
5 Ohta, H. and S. Katsuki, A new bariatric balloon capsule therapy without a filling tube indicates a reduction in visceral fat and insulin resistance. Gastroenterology, 2017. 152(5): p. S135.
6 Pryor, A., ., A 6-month swallowable balloon system results in sustainable weight loss at 1 year: Results from a prospective, randomized sham-controlled trial. Surgery for Obesity and Related Diseases, 2016. 12(7): p. S26–S27.
7 Rodríguez, G., ., A New Bariatric Procedure: The Stomach Sparing Gastric Sleeve™. Surgical technology international, 2015. 27: p. 116–122.26680388
8 Sivero, L., ., Treatment of morbid obesity with intragastric balloon: BioEnterics intragastric vs. Spatz adjustable balloon systems. Chirurgia (Turin), 2017. 30(2): p. 40–42.
9 Sullivan, S., ., The obalon swallowable 6-month balloon system is more effective than moderate intensity lifestyle therapy alone: Results from a 6-month randomized sham controlled trial. Gastroenterology, 2016. 150(4): p. S1267.
10 Thompson, C.C., ., The aspireassist is an effective tool in the treatment of class ii and class iii obesity: Results of a one-year clinical trial. Gastroenterology, 2016. 150(4): p. S86.
11 Thompson, C.C., ., Aspiration Therapy for the Treatment of Obesity: 2-4 Year Results of the PATHWAY Multicenter Randomized Controlled Trial. Surgery for Obesity and Related Diseases, 2018. 14(11): p. S4–S5.