# APPENDIX H OUTCOMES

Outcome | f/u Time (months) | # Studies | # RCTs | # nonRCTs
%TBWL | 6 | 19 | 7 | 12
%TBWL | 12 | 15 | 7 | 8
%EBWL | 6 | 8 | 7 | 1
%EBWL | 12 | 8 | 7 | 1
BMI | 6 | 8 | 6 | 2
total complication | 6 | 7 | 4 | 3
weight loss | 6 | 7 | 6 | 1
weight loss | 12 | 7 | 6 | 1
nausea/vomiting | 12 | 6 | 3 | 3
total complication | 12 | 6 | 3 | 3
BMI | 12 | 5 | 3 | 2
QOL | 6 | 5 | 3 | 2
infection | 12 | 5 | 2 | 3
GERD | 6 | 4 | 2 | 2
at least 10% total body weight | 6 | 4 | 3 | 1
at least 5% total body weight | 6 | 4 | 3 | 1
bleeding | 12 | 4 | 2 | 2
dehydration | 6 | 4 | 3 | 1
nausea/vomiting | 6 | 4 | 3 | 1
%TBWL | 24 | 3 | 0 | 3
30-day readmissions (time not specified) | 6 | 3 | 1 | 2
30-day reintervention | 12 | 3 | 1 | 2
QOL | 12 | 3 | 3 | 0
at least 10% total body weight | 12 | 3 | 3 | 0
at least 25% excess body weight | 12 | 3 | 3 | 0
at least 5% total body weight | 12 | 3 | 3 | 0
bleeding | 6 | 3 | 1 | 2
dehydration | 12 | 3 | 1 | 2
dyspepsia/abdominal pain | 6 | 3 | 3 | 0
dyspepsia/abdominal pain | 12 | 3 | 2 | 1
gastric ulceration | 6 | 3 | 3 | 0
HbA1C | 6 | 3 | 3 | 0
HbA1C | 12 | 3 | 2 | 1
30-day reintervention | 6 | 2 | 1 | 1
BMI | 24 | 2 | 0 | 2
GERD | 12 | 2 | 2 | 0
at least 25% excess body weight | 6 | 2 | 2 | 0
infection | 6 | 2 | 1 | 1
mortality | 12 | 2 | 1 | 1
weight loss | 24 | 2 | 1 | 1
%EBWL | 24 | 1 | 0 | 1
%EBWL | 36 | 1 | 0 | 1
%TBWL | 36 | 1 | 0 | 1
%TBWL | 120 | 1 | 1 | 0
30-day readmissions (only know within 90 days though) | 12 | 1 | 0 | 1
30-day readmissions (time not specified) | 12 | 1 | 1 | 0
30-day reintervention (don’t know time frame) | 12 | 1 | 0 | 1
BMI | 120 | 1 | 1 | 0
gastric ulceration | 12 | 1 | 0 | 1
improvement of diabetes | 12 | 1 | 1 | 0
improvement of hypertension | 12 | 1 | 1 | 0
weight loss | 60 | 1 | 1 | 0
weight loss | 120 | 1 | 1 | 0