# APPENDIX F QUALITY ASSESSMENT FOR INCLUDED OBSERVATIONAL STUDIES

Author, year | Bias due to confounding | Bias in selection of participants | Bias in classification of interventions | Bias due to deviations from intended interventions | Bias due to missing data | Bias in measurement of outcomes | Bias in selection of reported results
Abd El Mohsen, 2017^30^ | Unknown risk | Unknown risk | Low risk | Low risk | Low risk | Moderate risk | Low risk
Abeid, 2019^47^ | Low risk | Low risk | Low risk | Low risk | Low risk | Moderate risk | Low risk
Ahmed, 2019^42^ | Moderate risk | Moderate risk | Low risk | Low risk | Low risk | High risk | Low risk
Alqahtani, 2019^50^ | Low risk | Low risk | Low risk | Low risk | Low risk | Moderate risk | Low risk
Benias, 2020^37^ | Low risk | Moderate risk | Low risk | Low risk | Unknown risk | Moderate risk | Low risk
Cheskin, 2020^29^ | Low risk | Low risk | Low risk | Low risk | High risk | Moderate risk | Low risk
Espinet Coll, 2017^48^ | Low risk | Low risk | Low risk | Low risk | Low risk | Moderate risk | Low risk
Fayad, 2019^36^ | Moderate risk | Low risk | Low risk | Low risk | High risk | Moderate risk | Low risk
Fiorillo, 2020^34^ | Low risk | High risk | Low risk | Low risk | Low risk | Moderate risk | Low risk
Lopez-Nava, 2020^35^ | Low risk | Unknown risk | Low risk | Low risk | Low risk | Low risk | Low risk
Lopez-Nava, 2021^33^ | Low risk | High risk | Low risk | Low risk | Low risk | Moderate risk | Low risk
Mathus-Vliegen, 2015^45^ | Low risk | Moderate risk | Low risk | Low risk | Low risk | Moderate risk | Low risk
Novikov, 2018^32^ | High risk | High risk | Low risk | Low risk | Low risk | Moderate risk | Low risk
Raftopoulos, 2019^23^ | Moderate risk | Unknown risk | Low risk | Low risk | Unknown risk | Moderate risk | Low risk
Raftopoulos, 2019^24^ | Unknown risk | Unknown risk | Low risk | Low risk | Unknown risk | Moderate risk | Unknown risk
Sadek, 2017^43^ | Unknown risk | Unknown risk | Low risk | Low risk | Unknown risk | Moderate risk | Low risk
Salomone, 2021^57^ | Moderate risk | Low risk | Low risk | Low risk | Low risk | Moderate risk | Low risk
Sander, 2017^53^ | Low risk | Moderate risk | Low risk | Low risk | Low risk | Moderate risk | Low risk
Wilson, 2018^40^ | Low risk | Moderate risk | Low risk | Low risk | Low risk | Moderate risk | Low risk