# APPENDIX E QUALITY ASSESSMENT FOR INCLUDED RANDOMIZED CONTROLLED TRIALS

Author, year | Random sequence generation | Allocation concealment | Blinding of participants and personnel | Blinding of outcome assessment | Incomplete outcome data at 6, 12 months, longest | Selective reporting | Other sources of bias
Abu Dayyeh, 2015^13^ | Unknown risk | Unknown risk | High risk | High risk | High risk (70-75% follow up at1 year) | Low risk | Moderate risk
Abu Dayyeh, 2019^49^ | Unknown risk | Unknown risk | High risk | High risk | Low risk | Low risk | Moderate risk
Chan, 2021^59^ | Unknown risk | Unknown risk | High risk | High risk | Moderate risk | Low risk | Low risk
Courcoulas, 2017^20^ | Low risk (Trial is FDA approved) | Unknown risk | High risk | Unknown risk for weight; Unclear how weight measured; Moderate risk for QOL | Low risk at 9 months (80% follow up); High risk at 12 months (75% follow up) | Low risk | Moderate risk
Fuller, 2013^27^ | Unknown risk | Unknown risk | High risk | High risk | Low risk | Low risk | Moderate risk
Gomez, 2016^21^ | Low risk (Trial is FDA approved) | Unknown risk | High risk | Unknown risk for weight; Unclear how weight measured; Moderate risk for QOL; High risk for gastric emptying | Low risk (100% follow up) | High risk Weight is not primary endpoint of study | Moderate risk
Lee, 2012^58^ | Unknown risk | Unknown risk | Moderate risk | Moderate risk | Low risk | Low risk | Low risk
Mohammed, 3220^38^ | Unknown risk | Unknown risk | High risk | Moderate risk | Low risk | Low risk | Low risk
Ponce, 2013^26^ | Unknown risk | Unknown risk | Moderate risk | Moderate risk | Low risk | Low risk | Moderate risk
Ponce, 2015^28^ | Low risk | Low risk | Moderate risk | Moderate risk | Low risk | Low risk | Moderate risk
Raftoupoulos, 2019^24^ | Unknown risk | Unknown risk | High risk | High risk | High risk | Low risk | Low risk
Sullivan, 2012^41^ | Unknown risk | Unknown risk | High risk | High risk | Low risk | Low risk | Low risk
Sullivan, 2017^31^ | Low risk (Trial is FDA approved) | Unknown risk | Low risk | Unknown risk for weight Unclear how weight measured Moderate risk for QOL | Low risk | Low risk | Moderate risk
Sullivan, 2018^22^ | Low risk (Trial is FDA approved) | Unknown risk | Low risk | Unknown risk for weight Unclear how weight measured Moderate risk for QOL | Los risk | Low risk | Moderate risk
Thompson, 2017^39^ | Low risk (Trial is FDA approved) | Unknown risk | High risk | Unknown risk for weight Unclear how weight measured Moderate risk for QOL | High risk | Low risk | Moderate risk
Thompson, 2019^52^ | Low risk (Trial is FDA approved) | Unknown risk | High risk | Unknown risk for weight Unclear how weight measured Moderate risk for QOL | High risk | Low risk | Moderate risk