# APPENDIX B PEER REVIEW COMMENTS/AUTHOR RESPONSES

Reviewer # | Reviewer Comment | Authors Responses
1 | Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?; Yes - Abu Dayyeh BK, Maselli DB, Rapaka B, Lavin T, Noar M, Hussan H, Chapman CG, Popov V, Jirapinyo P, Acosta A, Vargas EJ, Storm AC, Bazerbachi F, Ryou M, French M, Noria S, Molina D, Thompson CC. Adjustable intragastric balloon for treatment of obesity: a multicentre, open-label, randomised clinical trial. Lancet. 2021 Nov 27;398(10315):1965–1973. doi: 10.1016/S0140-6736(21)02394-1. Epub 2021 Nov 15. Erratum in: Lancet. 2021 Nov 27;398(10315):1964. PMID: 3479374634793746 34793746 . | We have included this article in the updated search.
2 | Make sure that abbreviations are defined when first used.; a. For example, ESG should be defined on page 6 before it is used on page 7 | Completed.
2 | Page 8: The following line seems a bit awkward. “There are no studies assessing the durability of the weight loss with endoscopic therapies, such as at 5 years or even 10 years following the intervention, as does exist for some established surgical weight loss therapies (such as gastric bypass).”; a. Consider rephrasing the portion “such as at 5 year or even 10 years…” It may be better to drop the “or even 10 years”. I understand that you are trying to say that surgery has data out to 10 years, but the way it is written seems awkward. | Completed.
2 | Page 17: there is an error: “Error!…” | Thank you for this comment; there was a technical glitch and has been corrected.
2 | Page 27, line 8: This statement about statistical significance is a bit confusing. Consider revising to include this information in the earlier sentences on that page. I presume the 7.9% less improvement is the result that has no confidence interval. Since the other result is presented as non-significant, I don’t think that point merits repeating. | We adapted the description of these studies to make this more clear.
2 | Page 28, line 47: It would help the reader if the 1 reintervention was put in the context of the overall sample size. Is this one out of 10 participants or 1 out of 100, etc.? | Fixed.
2 | Page 28, lines 53-60 and all of page 29: Along the same lines, the discussion of abdominal pain and other adverse events is difficult to interpret without some information about the overall proportion and ideally, severity of the symptoms.; a. Table 2 should be called out on the prior page as this would have helped answer my question. The table would benefit from changing “Total Complications” to “Any Complication” and clarification that these are risk differences, not absolute rates of nausea, etc.; b. The analysis of adverse events doesn’t delve into any issues of severity or duration of these events. Many of these symptoms may be transitory as the patient adapts to the intervention. If nausea and vomiting require removal of the device, then that is much more important than a day or two of nausea immediately following the initial intervention. Even if it is not feasible to detail the severity and duration of symptoms, it would seem appropriate to acknowledge this as a limitation of the review. | We agree with the comments made by the reviewer. Most of the included studies do not detail severity or symptom specifics in regards to abdominal discomfort. Therefore we are limited in our ability to further characterize abdominal pain in our review.; We have added a statement regarding limitation of interpretation on page 28 as suggested.
2 | Page 29, Figure 8: This is labelled as “Total Complications” but then presented as risk differences. This is a bit confusing because “Total” makes it seem like this is a count of complications, but I suspect you mean “Any Complication”. As such, for the Thompson study, it would seem that almost 100% of the endoscopic group had a complication versus very few in the lifestyle group. Consider if there is a way to clarify this presentation through revision of the labels and/or adding explanatory text. | We have written a definition for total complications as a total of any complication in any patient.
2 | Page 37, line 6: This should read “Primary Obesity Surgery Endoluminal (POSE)” | Complete.
2 | Page 38, line 26: Consider revising as: “Financial impacts on closed…” | Complete.
2 | Page 39, line 47: The Conclusion states that endoscopic therapy is more effective than lifestyle, but has more complications. This is followed by a statement that surgery is probably more effective than endoscopy therapy but there is no mention of the increased risk of complications with surgery (ref 30). It would seem that this trade-off of risk/reward should also be clearly stated in the conclusion. This one aspect gives at least a hint of surgical bias in the presentation of the review. | We appreciate this input and have changed the sentence in conclusion to reflect the decreased relative adverse events rate of endoscopy as compared to surgery.
3 | Review for VA Evidence Synthesis Program Endoscopic bariatric interventions versus lifestyle interventions or surgery for weight loss in obese patients: A systematic review and meta-analysis; Overall, based on the available evidence I agree with the conclusions of the report. The report is limited by not including some of the registry studies, which for US data includes the largest number of patients and are likely more representative of clinical practice. For example, Moore RL. SOARD. 2019;15(3):417–423 included over 1300 patients from 108 practices with data collected and entered into the registry prospectively. However, I understand that the questions posed were specific to comparator groups, which is why registry data was not included. There were a few studies listed below that were not included in this analysis and there were some study populations that were reported more than once, which are outlined below. I would also highly recommend adding the data on safety included in FDA’s Summary of Safety and Efficacy Data for the Spatz3 balloon, which is can be found on FDA’s website (I can also provide you a PDF if you cannot find it). Although the data on non-serious adverse events wasn’t included in the abstract, all of that data is included in the SSED and it would be good if that can be included in the analysis. | On the updated search following submission, we are including the data in regards to the newly FDA-approved Spatz balloon which will include the data as suggested by the reviewer.
3 | Please change all language to people first: patients with obesity instead of obese patients. This is the required terminology for most obesity and bariatric surgery related journals as well as The Obesity Society and ASMBS. | Completed.
3 | Page 17 lines 20-21 include a grammatical error message, | Thank you for this comment; there was a technical glitch and has been corrected.
3 | Citations 14, 21, and 22 are from the same study population (IGB and control groups) | These references were continuations of a similar study population, for which we only included additional data for later published studies with longer followup. We were cognizant to not double count any overlapping data.
3 | Citations 31 and 33 are from the same patient population for ESG | These references were continuations of a similar study population, for which we only included additional data for later published studies with longer followup. We were cognizant to not double count any overlapping data.
3 | Citations 27 and 34 are from the same patient population for ESG (This may or may not be an issue because the comparator groups are different) | These references had overlapping study populations but we were cognizant to not double count any overlapping data.
3 | In table 2 and other points in the manuscript the Courcoulos 2017 study is incorrectly listed as Courcoulos 2005. | Complete.
3 | No studies of the ReShape balloon were included in the analysis. This balloon is no longer commercially available, but both a pilot study and randomized sham-controlled study took place in the US leading to FDA approval. The data support the use of intragastric balloons for weight loss, but would not otherwise change your conclusions. | We include FDA approved and currently available devices/techniques in this review.
3 | Randomized sham-controlled study design has been shown to reduce weight loss in endoscopic bariatric therapies ( Swei E. The American Journal of Gastroenterology. 2021;116:S584 ). While this doesn’t change your overall conclusions, it should be noted in your introduction and summary that this may limit the ability of this analysis to determine the full extent of efficacy since some of the studies included in this analysis were sham controlled. | We appreciate this insight and will address this in the methods.
3 | There are 2 randomized controlled trials for Aspire Assist. You are missing: Sullivan S. Gastroenterology. 2013;145(6):1245–1252 24012983 | This title was included in our updated search but has been excluded as it is a pilot study of a later Sullivan RCT of AspireAssist patients with likely patient overlap.
3 | Reference 36 is not an RCT. It is a comparative analysis. | We have updated this in our study.
3 | Page 28 line 19, this should be reference 36 | We have confirmed that this reference is appropriate
3 | Reference 26 is only an abstract. The full data can be seen on the FDA’s Summary of Safety and Effectiveness Data report for the Spatz3 balloon, which is available publicly on line. I understand this got approval one week before completing this report. If possible this data should be included in all of the sections on AE outcomes in Key Question 2 indicating data is available for these outcomes in 3 studies. | We have added these data to our study.
3 | Page 28 line 46 – I don’t believe this is the correct reference. | We have changed the reference to the appropriate study.
3 | Page 29 line 5, I believe 36 is the incorrect reference | We have changed the reference to the appropriate study.
3 | Page 29 line 14. There was one bleeding event in the study of reference 23. That should be noted since the rate is 0.3% compared with 0%, which actually may not reach statistical significance. | Thank you for the reference and we have adjusted the results in the manuscript.
3 | Page 32 paragraph 2. There is a comparative analysis of Obera vs Obalon balloon: Almuh aidb A. Comparison of the efficacy and safety of the FDA-Approved Intragastric Balloon systems in a clinical setting. Gastrointestinal Endoscopy. 2020;91(6):AB222 . | We excluded studies that compared endoscopic to endoscopic therapies given that this was beyond the scope of this query.
4 | Very nicely done. This will be a helpful addition to the literature. Some suggestions for improvements:; General - Many organizations and journals are trying to move away from the phrase “obese patients” or “obese adults” and instead use “patients with obesity.” For example, in the title, would rephrase to “patients with obesity.” There are numerous places in the manuscript too. | Complete.
4 | Terminology - Instead of “surgical bariatric therapy” would just say “bariatric surgery”; I get that you’re drawing a comparison to “endoscopic bariatric therapy,” but that term is awkward. | Complete.
4 | Are you comparing endoscopy to surgery and “lifestyle modification” only? What about pharmacologic therapy? This typically would not be considered in the same boat as behavior weight management, which typically includes dietary and physicial activity changes. Would be clear about these therapies throughout. In my mind, there are 4 therapies: behavioral weight management, pharmacologic, endoscopic, and surgery. Also, would use the term “pharmacologic” since previous obesity workgroups (e.g., Weight Management SOTA in 2015) used the terminology “pharmacologic” | We agree that pharmacotherapy is a crucial part of management. We did not find any randomized or comparative studies directly studying endoscopic methods to pharmacotherapy in our search. This is a key question that should be explored further in future research.
4 | Data abstraction - Who was involved in the “full group discussion”? | Phan, Shekelle, Weitzner, Gibbons, Girgis
4 | Exec summary Intro - Is that economic burden in the US alone? | Yes the burden is in regards to the United States alone.
4 | Rationale for excluding studies where similar mechanisms were compared to one another (balloon vs. balloon). Wouldn’t data from those participants still be useful in a meta-analysis? | We agree that comparing similar mechanisms is valuable, as it warrants investigation in future papers. However, this was outside the scope of our paper for the purposes of TEP review.
4 | I like including the main outcome as % TWL as opposed to another metric such as % EWL. The first figure is excellent. | We appreciate this feedback.
4 | Key question 2 - “more total complications…..” in which group? | Completed.
4 | Research gap - Can you be more specific about a “prior version of the gastric balloon.” Are you referring to laparoscopic adjustable gastric banding or another type of endoscopically placed intra-gastric balloon? LAGB has not been “removed” although it is much lower in frequency than it was previously. | Thank you for the comments, clarification has been added to the research gaps.
4 | Literature flow - There is a comment that includes “Error!” | Thank you for this comment; there was a technical glitch and has been corrected.
4 | The interpretation of Table 1 is challenging. It’s not immediately clear what the mean difference in hemoglobin and QoL represents. For QoL, presumably a higher number means QoL is higher for IGB compared to lifestyle? It’s not clear if these scales are all the same. For HgbA1c diff, a higher number would presumably be bad for IBG because it would imply that post-intervention HbgA1c is higher than that of lifestyle? The interpretation is quite challenging here. Would consider just describing this in the text. | We have clarified this for the reader.
4 | Same with Table 2. I struggle with interpretability. Maybe it would be helpful to add a legend describing what a couple of numbers in the various cells means. | A legend has been added to help explain table values.
4 | The authors note that “the history of weight loss interventions is one of innovation and dissemination prior to evaluation.” This seems misleading and inaccurate. Yes, there are some examples that the authors highlight. There is also a 30+ year history of a lack of D&I of evidence-based obesity treatment - including the 2 gold standard operations (lap sleeve and lap bypass) and numerous FDA-approved obesity medications such that we’re severely underutilizing evidence-based obesity treatments in the U.S. I think it’s totally justifiable to cite those examples (VBG, LABG?, phenteramine) as interventions within the field where evidence was lacking prior to D&I, but would not characterize the entire field of obesity treatment (meds, bariatric surgery) as fitting that description. | Thank you for this comment; the statement has been rephrased.
1 | The authors are to be congratulated on this important and well-executed systematic review and meta-analysis. Given the rapid increase in obesity over the past few decades, and projected further increase in obesity, new interventions available to veterans are needed. Amongst the currently available options, bariatric surgery appears to be the most effective in reducing weight and improving metabolic comorbidities in the long term, however, its uptake is limited due to perceived surgical risks and limited access. A new class of interventions that are less invasive than surgery, endoscopic bariatric therapies (EBTs), have become available to veterans in recent years. This systematic review focuses on a few specific questions related to the efficacy of FDA-approved EBTs, looking at studies published since 2014. These include two of the four FDA-approved intragastric balloons(IGBs), Orbera and Obalon; aspiration therapy, and endoscopic gastroplasty (not approved for treatment of obesity but device approved for use). Another balloon that was approved in 2015, the Reshape balloon, currently is not available in the US. A fourth balloon, the Spatz balloon, was approved in October 2021, but data was published after this review was completed. However, the pivotal trial results were presented as an abstract in 2018-2019, and likely should have been included. The FDA submission documents were also available for review since earlier in 2021.; Overall, well-executed review looking at three questions:; Key Question 1 What Is the Comparative Effectiveness Of Endoscopic Bariatric Interventions Versus Lifestyle Interventions Or Bariatric Surgery?; Key Question 2 What Are the Comparative Harms Of Endoscopic Bariatric Interventions Versus Lifestyle Interventions Or Bariatric Surgery?; Key Question 3 Do The Comparative Effectiveness And/Or Harms Vary By Patient Or Intervention Characteristics(ie, Age, BMI, Type Intragastric Balloon, Gastroplasty Technique, etc)? | Thank you for this comment. We have included the Spatz balloon in our updated review after its approval.
| Given the general lack of RCTs involving EBTs, I would recommend including the recently published high quality RCT of Spatz balloon in this meta-analysis. PMID 34793746 | This study has been included in our updated search.
| The authors have used overlapping data of three presentations looking at the same IGB trial population: References 14,20,21 are all presentations of data from the Orbera pivotal trial, here presented as different studies. I would argue that this may be allowed if they document complimentary data, such as reporting different adverse events, but would not use them separately to report the same outcome measure such as weight loss or nausea, for example. | These references had overlapping study populations but we were cognizant to not double count any overlapping data.
| References 1 and 12 are the same. | Thank you for catching this error. The references have been changed.
| Additionally, ref 1/12 and 30 have overlapping patients; 1/12, 30 and 43 – same. | These references had overlapping study populations but we were cognizant to not double count any overlapping data.
| Regarding Figures 2 and 6, I am not sure why the authors decided to pool both surgery and lifestyle as comparators to EBTs. I would argue that these should be two different figures : 2a and 2b, and 6a and 6b,with lifestyle and surgery, respectively. | The data are not pooled, just displayed on the same graph to allow better visual interpretation.
| The adverse events associated with Orbera and Obalon differ widely, and one could argue that they should be analyzed separately and not pooled together. Rate of serious adverse events (SAE) with fluid-filled gastric balloons such as Spatz, Reshape and Orbera, is reported to be around 10%, while rate of SAE with Obalon(gas-filled) is 0.2%. To me, it is not clinically relevant to pool these together in the same meta-analysis. Rather, these should be discussed separately in comparison to lifestyle or surgery. | While each procedure has its own benefits and shortcomings, the scope of our review was to compare overall effects of treatment types in comparison to each other. Further studies can tease out these nuances.
| Since the approval of semaglutide, weight loss medications have become a viable option for treatment of obesity, apparently similar in efficacy to the EBTs, with its own set of adverse events, cost issues, and attrition rate. Additionally, combination of GLP-1 and GIP-agonists are pending and expected next year. Thus, weight loss medications should be included in the discussion of future directions for studies. | We agree and have included the importance of pharmacotherapy in the future directions.
| Some data from outside of the US points to a beneficial more sustained effect of EBTs in patients with lower BMIs in the overweight range. Thus, studies of early weight reduction interventions in patients who are overweight and at risk for metabolic decompensation could represent a future direction. | We agree, but aimed this review at those who qualify for procedures in the US. Future studies can address this.
| Finally, in our experience, combination therapies involving EBTs and weight loss medications may be a viable long-term option for patients unwilling to undergo surgery. We use IGB of ESG as a tool for selected patients as part of a lifelong obesity therapy with an initial weight reduction that, in turn, could positively influences lifestyle choices and allow weight stabilization in the long term. | We agree and have expanded this in our discussion.