# ABBREVIATIONS TABLE

Abbreviation: Name
AGB: Adjustable Gastric Band
ASMBS: American Society of Metabolic and Bariatric Surgery
BMI: Body Mass Index
DM: Diabetes Mellitus
EBW: Excess Body Weight
EBWL: Excess Body Weight Loss
ESG: Endoscopic Sleeve Gastroplasty
FDA: US Food and Drug Administration
GRADE: Grading of Recommendations Assessment, Development and Evaluation working group
GERD: Gastroesophageal Reflux Disease
HTN: Hypertension
IGB: Intragastric Balloon
LAGB: Laparoscopic Adjustable Gastric Banding
LSG: Laparoscopic Sleeve Gastrectomy
LOS: Length of Stay
NAFLD: Nonalcoholic fatty liver disease
NH: Non-Hispanic
POSE: Primary Obesity Surgery Endolumina
RCTs: Randomized controlled trials
ROBINS-I: Cochrane Risk of Bias In Non-randomized Studies – of Interventions
RYGB: Roux-en-Y Gastric Bypass
TBWL: Total Body Weight Loss
QOL: Quality of Life