# ACKNOWLEDGMENTS

The authors are grateful to Kathryn Vela, MLIS for literature searching, Payten Sonnen for editorial and citation management support, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- David Atkins, MD, MPH
  Director
  VA Health Services Research and Development Service
- Chad Kessler, MD, MHPE
  Director, Emergency Medicine
  VA Office of Specialty Care Services
- Karen Bossi, MA
  Portfolio and Special Projects Coordinator
  VA Center for Information Dissemination and Education Resources
- Anita Vashi, MD, MPH, MHS
  Lead, Emergency Medicine SOTA Workgroup
  VA Palo Alto Healthcare System
- Kristin Mattocks, PhD, MPH
  Lead, Emergency Medicine SOTA Workgroup
  VA Central Massachusetts Healthcare System

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix F in Supplemental Materials for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.