# DISCUSSION

The purpose of this report was to identify, classify, and organize the broad body of research on interventions to improve patient transition across health care settings and systems. Outcomes related to ED and hospital utilization were the most common, followed by measures of follow-up or engagement with outpatient providers. Overall, included interventions were as or more effective than comparison conditions (typically usual care). However, the findings from a qualitative study of care coordination between VHA and community settings for Veterans with COPD underscored the importance of effective communication, and the need for system-level solutions to avoid duplicative tests (eg, imaging) and other wasted resources. Common patient-reported barriers included challenges related to scheduling follow-up appointments and those related to access, such as transportation and child care. Barriers across settings highlight the challenges of sharing protected information across health systems – especially when interventions are not aligned with workflow and lack staff and provider buy-in.

## LIMITATIONS

There are a number of limitations to this Evidence Map. To illustrate the evidence, we categorized the patient population as belonging to 1 of 4 groups. Our categories were determined by population categories available across included studies. We recognize that patients may fall into more than 1 group, and that our categorization may not well represent the heterogeneity within each group. None of the 13 studies conducted in VHA settings were specific to discharge from the ED. These studies were considered important to include because of the unique nature of the VHA as a centralized health system, and the applicability to the transition between community settings and VHA outpatient care. However, some aspects may be less applicable due to differences in departmental workflow and other factors.

## FUTURE RESEARCH

This report was intended to broadly describe the state of the evidence examining cross-system care transitions from the ED to outpatient settings within the context of an implementation framework. There are several promising areas for future research. The evidence suggests primary research is needed on patient outcomes of care transition interventions and on interventions to mitigate frequent ED use. Additionally, the systematic review we identified included only ED-based RCTs, and a future evidence review that includes observational and quality improvement studies is warranted to provide a more complete picture of available evidence on system-level interventions. We also identified a moderately sized body of qualitative research exploring barriers and facilitators to successful cross-system care transitions. Although formal theme analysis was outside of the scope of this report, we identified overlap in key findings across these studies. A systematic review augmented by VHA stakeholder interviews investigating common themes from qualitative research on this topic would likely provide important insights for implementing care transition interventions in the VHA context.