# RESULTS

## LITERATURE FLOW

The literature flow diagram (Figure 2) summarizes the results of the study selection process (full list of excluded studies available in Appendix C in Supplemental Materials).

Figure 2 Literature Flowchart

Abbreviations. CDSR=Cochrane Database of Systematic Reviews; SR=systematic review

## LITERATURE OVERVIEW

Our search identified 5,541 potentially relevant articles. We included 50 studies: 1 systematic review4 and 49 primary studies.^1,2,7–53^ Twenty-four studies^1,10–14,18,22,24,26,28,29,32–34,36–38,41,46–50^ reported intervention outcomes of care transition interventions and 28 studies^1,2,7–9,15–17,19–25,27,30,31,35,39,40,42–45,51–53^ reported information on barriers and facilitators to care transitions (not mutually exclusive). Figure 3 characterizes the included primary studies. Most studies were in the US and included interventions targeted to the general ED population. The identified systematic review^4^ included 35 studies examining the effect of ED-based care transition interventions on outpatient follow-up rates, ED utilization, and patient satisfaction. We identified 3 underway or unpublished studies examining the effects of emergency department-based interventions in facilitating transition to outpatient care (see Appendix E in Supplemental Materials).

Figure 3 Primary Study Characteristics

Note. Study counts are not mutually exclusive.

Abbreviations. ED=emergency department; MH=mental health; SUD=substance use disorder

## INTERVENTION CHARACTERISTICS

Of the 24 studies reporting outcomes of interest, 8 were trials, 6 were prospective observational studies, 8 were retrospective observational or cross-sectional studies, and 2 were qualitative studies. For the systematic review, the authors rated the strength of evidence for all conclusions as low.^4^ Figure 4 illustrates the reported findings of the systematic review and primary studies by population and outcome (see Appendix D in Supplement Materials for full study details).

Six studies were conducted in VHA settings.^1,10,18,26,33,47^ Five interventions targeted older adults,^13,28,29,41,46^ 2 were for patients with patterns of high ED utilization,^14,38^ and the remaining were for general or other populations. There were 21 studies^10–14,18,24,26,28,29,32–34,36–38,41,46,48–50^ reporting outcomes related to utilization, 15 studies^1,10,11,18,22,24,26,29,32,34,36,38,47,48,50^ that reported intermediate outcomes, and 3 studies reporting patient outcomes.^13,41,48^ Utilization-related outcomes were primarily ED revisits and hospital admissions at different end points. Follow-up with primary care was the predominant intermediate outcome reported. Only 1 study,^1^ examining care transitions for Veterans with COPD, reported the ordering of duplicate tests. Reported patient outcomes were 30-day mortality^13,41^ and patient satisfaction^48^ (Appendix D in Supplement Materials provides more detail).

Figure 4 ED to Outpatient Care Transition Study Characteristics and Reported Effects

Eleven studies reported barriers or facilitators that were a characteristic or component of an intervention. Four studies were conducted in VHA outpatient settings,^9,23,35,39^ 2 studies targeted high ED utilizing patients,^15,30^ 1 study targeted ED patients seen for opioid use disorders,^27^ 1 focused on older adults,^16^ and 3 studies were of general or other patient populations.^7,21,45^ Figure 5 details the barriers and facilitators identified in these studies. Three of the 11 studies were of Health Information Exchanges (HIEs),^7,23,35^ 2 of which were in VHA settings.^23,35^ One study examined intensive case management.^30^ The remaining 7 studies examined general care coordination or were non-specific (see Appendix D in Supplemental Materials for more detail). Only 1 study explored differences by patient characteristics. It reported no differences in the odds of scheduling a follow-up appointment by insurance status, including Medicaid, and age over 65 years.^37^

Figure 5 Intervention Barriers and Facilitators

Abbreviations. ED=emergency department; EHR=electronic health record; VHA=Veterans Health Administration; PCP=primary care provider

## IMPLEMENTATION PROCESSES

We identified 11 studies that reported barriers or facilitators related to implementation processes. Three studies were conducted in VHA outpatient settings,^1,19,35^ 1 study examined care transitions for high ED utilizing patients,^30^ 2 studies were of patients presenting to the ED with mental health or substance use disorders,^27,42^ 1 study examined older adults,^16^ and 3 studies included general or other populations.^2,7,31^ Figure 6 details the barriers and facilitators identified in these studies.

Of the studies that specified an intervention, 5 examined HIEs,^7,19,23,35,40^ 2 were of intensive case management,^30,42^ 2 focused specifically on provider communication,^2,31^ and 1 targeted Veterans with chronic obstructive pulmonary disease (COPD)^1^ (see Appendix D in Supplemental Materials for more detail).

Figure 6 Implementation Barriers and Facilitators

Abbreviations. HIE=health information exchange; MA=medical assistant; VHA=Veterans Health Administration.

## OUTER SETTING

There were 11 studies that included barriers or facilitators related to the outer setting. One study examined Veterans in a VHA setting,^20^ 2 studies were of patients with mental health or substance use disorders,^27,52^ 1 was of patients with a history of high ED utilization,^15^ and 1 study focused on older adults.^25^ All other studies were of general or other populations.^8,17,22,24,43,45,53^ One study focused on a HIE in a VHA setting.^20^ All others were non-specific (see Appendix D in Supplemental Materials for more detail). Figure 7 details the barriers and facilitators identified in these studies.

## INNER SETTING

We identified 13 studies that reported barriers or facilitators related to the inner setting. Ten studies focused on outpatient settings,^8,9,19,22,25,30,43–45,51^ 1 study described barriers related to the transition from a community setting to a VHA patient-aligned care team (PACT),^39^ and 2 studies applied to both EDs and outpatient settings.^24,27^ Two of the 10 outpatient focused studies were conducted in the VHA,^9,19^ 1 study focused on an intervention for older adults,^25^ and the remaining 7 studies were of care transitions for general or other populations.^8,21,22,43–45,51^ Only 2 studies were of specific interventions, 1 of which was HIE,^19^ the other intensive case management^30^ (see Appendix D in Supplemental Materials for more detail). Figure 7 details the barriers and facilitators identified in these studies.

## CHARACTERISTICS OF INDIVIDUALS

Fourteen studies report barriers or facilitators related to personal characteristics of health care providers/staff (6 studies)^1,2,7–9,45^ and/or patients (10 studies).^8,15–17,20,21,42,44,45,52^ Two studies were of providers/staff in VHA settings,^1,9^ and 1 study applied to Veterans^20^ (see Appendix D in Supplemental Materials for more detail). Figure 7 details the barriers and facilitators identified in these studies.

Figure 7 Outer Setting, Inner Setting, and Individual-level Barriers and Facilitators

Abbreviations. ED=emergency department; HIE=health information exchange; PPO=preferred provider organization; SES=socio-economic status