# METHODS

## KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ1 What implementation factors impact the benefits and harms of transition of care from emergency departments (EDs) in 1 health system to outpatient care settings in another?
  KQ1a Does the implementation of transition of care interventions differ by patient characteristics (eg, clinical severity, demographics, level of emergency care utilization)?

## ELIGIBILITY CRITERIA

The ESP included studies that met the following criteria:

Population | Any adult discharged from the emergency department to outpatient care and Veterans discharged from a community EDs or inpatient setting to VHA outpatient care.
Intervention | Interventions will be those that include “a set of actions designed to ensure the coordination and continuity of health care as patients transfer between different locations or different levels of care”.^5^ With the exception of studies examining interventions for the transition from community settings to the VHA, all interventions must focus on the transition from the emergency department to outpatient care. For studies examining Veterans transitioning to the VHA, interventions may focus on the transition from the emergency department or inpatient settings to VHA outpatient care. All interventions must involve the transition from 1 health system to another. Interventions can take place before or after discharge and may include components that span settings.
Comparator | Usual care or other interventions.
Outcomes | - Patient outcomes: Mortality, patient satisfaction; - Intermediate outcomes: Over- or inappropriate prescribing, duplicate tests or imaging, follow-up by primary care (# days), purpose of tests or images ordered in the ED are clear; - Utilization: ED utilization (up to 1 year), inpatient admission (direct or via ED) within 30 days of last ED visit, ambulatory care sensitive hospitalizations within 30 days; - Barriers and facilitators to care transitions
Timing | Primarily ≤ 30 days. Up to 1 year for outcomes related to frequent utilization.
Setting | Non-VHA emergency departments in the US, Canada, and Europe. We will include both integrated and non-integrated care settings.
Study Design | Any, but we may prioritize articles using a best-evidence approach to accommodate Evidence Map timeline.

## DATA SOURCES AND SEARCHES

To identify articles relevant to the key questions, a research librarian searched Ovid MEDLINE, Embase, and ClinicalTrials.gov, as well as AHRQ, Cochrane Database of Systematic Reviews, and HSR&D through September 10, 2021 using terms for emergency department, care coordination, care transitions, and discharge (see Appendix A in Supplemental Materials for complete search strategies). Additional citations were identified from hand-searching reference lists and consultation with content experts. To identify additional articles examining care transitions from community to outpatient VHA settings, we conducted a targeted hand search of reference lists and searched terms for health information exchange. We limited the search to published and indexed articles involving human subjects available in the English language. Study selection was based on the eligibility criteria described above. Titles, abstracts, and full-text articles were reviewed by 1 investigator and checked by another. All disagreements were resolved by consensus or discussion with a third reviewer.

## DATA ABSTRACTION AND ASSESSMENT

From each study we abstracted data related to study design, number of participants, setting, population, intervention and comparator characteristics, outcomes, whether the reported intervention effect was positive, equal, or negative, as well as barriers and facilitators to successful ED to outpatient transitions. From systematic reviews, we abstracted the number of studies, number of participants, relevant findings, and reported strength of evidence. All data abstraction was first completed by 1 reviewer and then checked by another; disagreements were resolved by consensus or discussion with a third reviewer. Given that the purpose of our review was to identify and classify the broad body of research related to care transition interventions, we did not formally assess the quality of individual studies.

## SYNTHESIS

We provide an Evidence Map illustrating outcomes research in the care transitions literature and provide figures summarizing barriers and facilitators. Findings are organized using the Consolidated Framework for Implementation Research (CFIR) domains of intervention characteristics, outer setting, inner setting, characteristics of individuals, and implementation processes (see Figure 1 and Appendix B in Supplemental Materials).^6^

An Evidence Map is a bubble plot that provides information in 6 dimensions: quadrant, x-axis, y-axis, bubble color, bubble size, and bubble shape. Table 1 outlines the data element and categories for each dimension. Patient population categories were determined by the available population categories across included studies. When a study could have been categorized into more than 1 group, we selected the group that represented the target population of the intervention. The population for all studies conducted in VHA outpatient settings were coded as Veterans.

Table 1 Evidence Map Dimensions, Data Elements, and Categories

Dimension | Data Element | Categorization
Quadrant | Population | 1) Veterans, 2) High ED Utilizing Patients, 3) Older Adults, 4) General/Other
x-axis | Outcomes | 1) Utilization, 2) Intermediate Outcomes, 3) Patient Outcomes
y-axis | Reported Effect | 1) Positive Effect, 2) No Effect or Equal, 3) Negative Effect
Bubble Size | Sample Size | 1) < 200, 2) 200-999, 3) 1000-4999, 4) ≥ 5000
Bubble Color | Study Design | 1) Trials, 2) Prospective Observational, 3) Other Observational, 4) Qualitative
Bubble Shape | Study Type | 1) Primary Study, 2) Systematic Review

Note. Trials includes non-randomized clinical trials as well as randomized controlled trials (RCTs).

Abbreviation. ED=emergency department

Figure 1 Consolidated Framework for Implementation Research

Note. See Appendix B in Supplemental Materials for definitions.

Abbreviation. ED=emergency department