# INTRODUCTION

## PURPOSE

The ESP Coordinating Center (ESP CC) is responding to a request from VA’s Health Services Research and Development Service (HSR&D) for an Evidence Map on implementation factors that influence the effectiveness of emergency department (ED) to outpatient transitions of care across health systems. Findings from this Evidence Map will be used to inform a January 2022 State-of-the-Art (SOTA) conference on emergency medicine.

## BACKGROUND

Transitions of care between different health care settings present a range of challenges to the management and continuity of care, such as electronic health record (EHR) interoperability^1^ and miscommunication between providers.^2^ Patients transitioning from the ED to outpatient care across health care settings are especially vulnerable, as they are likely recovering from injuries or acute illness and being treated by a new provider with limited access to their medical history.^3^

A recent systematic review examined the effect of interventions for improving the transition between the ED and outpatient care on the rate follow-up visits, ED revisits, and hospital admission after ED discharge.^4^ However, the systematic review included only RCTs and only ED-based interventions. This report aims to provide a broad overview of available research on interventions to improve transitions from ED to outpatient care settings (in the form of an Evidence Map), and to summarize the findings of research examining care transition-related barriers and facilitators.