# EXECUTIVE SUMMARY

### Background

The Evidence Synthesis Program Coordinating Center is responding to a request from VA’s Health Services Research and Development Service (HSR&D) for an Evidence Map on implementation factors that influence the effectiveness of emergency department to outpatient transitions of care across health systems. Findings from this Evidence Map will be used to inform a January 2022 State-of-the-Art (SOTA) conference on emergency medicine.

### Methods

To identify studies, we searched MEDLINE®, Cochrane Database of Systematic Reviews, and other sources up to September 2021. We used prespecified criteria for study selection and data abstraction. We provide an Evidence Map and organize findings using the Consolidated Framework for Implementation Research (CFIR) domains of intervention characteristics, outer setting, inner setting, characteristics of individuals, and implementation processes. See the Methods section for full details of our methodology.

Key Findings

- Twenty-four studies reported outcomes related to care utilization, intermediate outcomes, or patient outcomes. Six were conducted in VHA outpatient settings. Only 3 studies examined patient outcomes. All but 1 study reported that interventions were as or more effective than comparison conditions (typically usual care).
- Eleven studies reported barriers related to intervention characteristics. Two were conducted in VHA settings. Common among community providers was difficulty identifying patients as Veterans. Both community providers and Veterans reported challenges related to VA formulary. In other settings, patients perceived very little or no communication between providers.
- Eleven studies reported barriers related to implementation processes. In the 3 studies conducted in VHA settings, barriers included concerns about workflow, differences in stakeholder priorities, and time. In other settings workflow was also a concern, as were time and inefficiency.
- Only 1 of the 11 studies related to the outer setting was conducted in the VHA. Common across studies were barriers related to rural residence, and lack of transportation, childcare, and insurance.
- Thirteen studies reported barriers related to the inner setting, 3 of which were performed in VHA settings. Across settings, components of the organizational culture served as barriers and patients found obtaining a follow-up appointment challenging.
- Of the 14 studies reporting barriers related to characteristics of individuals, 2 were of Veterans or VHA providers/staff. Patient-reported barriers included trust, time, and stage of change. Providers reported feeling uninformed and expressed concerned about increased workload.
- Future studies of interventions to mitigate frequent ED use are needed, as are investigations of patient outcomes across key populations.
- Future systematic reviews should include observational and quality improvement studies. In addition, a systematic review augmented by VHA stakeholder interviews investigating common themes from qualitative research on this topic may provide important insight for implementation.

Transitions between different health care settings present a range of challenges to the management and continuity of care, such as electronic health record (EHR) interoperability and miscommunication between providers. Patients transitioning from the ED to outpatient care across health care settings are especially vulnerable, as they are likely recovering from injuries or acute illness and being treated by a new provider with limited access to their medical history. This report aims to provide an overview of available research on interventions to improve transitions from emergency to outpatient care settings (in the form of an Evidence Map), and to summarize the findings of research examining care transition-related barriers and facilitators.

Table ES1 Evidence Map Dimensions, Data Elements, and Categories

Dimension | Data Element | Categorization
Quadrant | Population | 1) Veterans, 2) High ED Utilizing Patients, 3) Older Adults, 4) General/Other
x-axis | Outcomes | 1) Utilization, 2) Intermediate Outcomes, 3) Patient Outcomes
y-axis | Reported Effect | 1) Positive Effect, 2) No Effect or Equal, 3) Negative Effect
Bubble Size | Sample Size | 1) < 200, 2) 200-999, 3) 1000-4999, 4) ≥ 5000
Bubble Color | Study Design | 1) Trials, 2) Prospective Observational, 3) Other Observational, 4) Qualitative
Bubble Shape | Study Type | 1) Primary Study, 2) Systematic Review

Note. Trials includes non-randomized clinical trials as well as randomized controlled trials (RCTs).

Abbreviation. ED=emergency department

Figure ES1 Consolidated Framework for Implementation Research

Note. See Appendix B in Supplemental Materials for definitions.

Abbreviation: ED=emergency department

We identified 24 studies examining ED to outpatient care transition interventions. Outcomes related to ED and hospital utilization were the most commonly reported, followed by measures of follow-up or engagement with outpatient providers. Overall, included interventions were as or more effective than comparison conditions (typically usual care). However, the findings from a qualitative study of care coordination between VHA and community settings for Veterans with COPD underscores the importance of effective communication, and the need for system-level solutions to avoid duplicative tests (eg, imaging) and other wasted resources. Common patient-reported barriers included challenges related to scheduling follow-up appointments and those related to access, such as transportation and child care. Barriers across settings highlight the challenges of sharing protected information across health systems – particularly when interventions are not aligned with workflow and lack staff and provider buy-in.

Figure ES2 ED to Outpatient Care Transition Study Characteristics and Reported Effects

There are a number of limitations to this Evidence Map. To illustrate the evidence, we categorized the patient population as belonging to 1 of 4 groups. Our categories were determined by population categories available across included studies. We recognize that patients may fall into more than 1 group, and that our categorization may not well represent the heterogeneity within each group. None of the 13 studies conducted in VHA settings were specific to discharge from the ED. These studies were considered important to include because of the unique nature of the VHA as a centralized health care system, and the applicability to the transition between community settings and VHA outpatient care. However, some aspects may be less applicable due to differences in departmental workflow and other factors.