# REFERENCES

1 Aghajafari F, Sayed S, Emami N, Lang E, Abraham J. Optimizing emergency department care transitions to outpatient settings: A systematic review and meta-analysis. American Journal of Emergency Medicine. 2020;38(12):2667–2680.
2 Ayele RA, Liu W, Rohs C, . VA Care Coordination Program Increased Primary Care Visits and Improved Transitional Care for Veterans Post Non-VA Hospital Discharge. American Journal of Medical Quality. 2021;36(4):221–228.32772849
3 Dixon BE, Judon KM, Schwartzkopf AL, . Impact of event notification services on timely follow-up and rehospitalization among primary care patients at two Veterans Affairs Medical Centers. Journal of the American Medical Informatics Association. 2021.
4 Hastings SN, Stechuchak KM, Coffman CJ, . Discharge Information and Support for Patients Discharged from the Emergency Department: Results from a Randomized Controlled Trial. Journal of General Internal Medicine. 2020;35(1):79–86.31489559
5 Lovelace D, Hancock D, Hughes SS, Wyche PR, Jenkins C, Logan C. A Patient-Centered Transitional Care Case Management Program: Taking Case Management to the Streets and Beyond. Professional Case Management. 2016;21(6):277–290.27749704
6 Sherman RL, Judon KM, Koufacos NS, . Utilizing a health information exchange to facilitate COVID-19 VA primary care follow-up for Veterans diagnosed in the community. JAMIA open. 2021;4(1):ooab020.33748690
7 Bodenmann P, Velonaki VS, Griffin JL, . Case Management may Reduce Emergency Department Frequent use in a Universal Health Coverage System: a Randomized Controlled Trial. J Gen Intern Med. 2016;32(5):508–515.27400922
8 Nossel IR, Lee RJ, Isaacs A, Herman DB, Marcus SM, Essock SM. Use of Peer Staff in a Critical Time Intervention for Frequent Users of a Psychiatric Emergency Room. Psychiatr Serv. 2016;67(5):479–481.26766759
9 Biese KJ, Busby-Whitehead J, Cai J, . Telephone Follow-Up for Older Adults Discharged to Home from the Emergency Department: A Pragmatic Randomized Controlled Trial. Journal of the American Geriatrics Society. 2018;66(3):452–458.29272029
10 Hwang U, Dresden SM, Rosenberg MS, . Geriatric emergency department innovations: transitional care nurses and hospital use. Journal of the American Geriatrics Society. 2018;66(3):459–466.29318583
11 Jacobsohn GC, Jones CMC, Green RK, . Effectiveness of a care transitions intervention for older adults discharged home from the emergency department: A randomized controlled trial. Academic Emergency Medicine. 2021;26:26.
12 Pedersen LH, Gregersen M, Barat I, Damsgaard EM. Early geriatric follow-up visits to nursing home residents reduce the number of readmissions: a quasi-randomised controlled trial. Eur Geriatr Med. 2018;9(3):329–337.34654236
13 Schumacher JR, Lutz BJ, Hall AG, . Impact of an Emergency Department-to-Home Transitional Care Intervention on Health Service Use in Medicare Beneficiaries: A Mixed Methods Study. Medical Care. 2021;59(1):29–37.33298706
14 Bauer KL, Sogade OO, Gage BF, Ruoff B, Lewis L. Improving Follow-up Attendance for Discharged Emergency Care Patients Using Automated Phone System to Self-schedule: A Randomized Controlled Trial. Academic Emergency Medicine. 2021;28(2):197–205.32654257
15 Bell LC, Norris-Grey C, Luintel A, . Implementation and evaluation of a COVID-19 rapid follow-up service for patients discharged from the emergency department. Clinical Medicine. 2021;21(1):e57–e62.33355255
16 Foster SD, Hart K, Lindsell CJ, Miller CN, Lyons MS. Impact of a low intensity and broadly inclusive ED care coordination intervention on linkage to primary care and ED utilization. American Journal of Emergency Medicine. 2018;36(12):2219–2224.
17 Galarraga JE, DeLia D, Wilhite D, . Emergency department care coordination strategies and perceived impact under Maryland’s hospital payment reforms. American Journal of Emergency Medicine. 2021;45:578–589.
18 Losonczy LI, Hsieh D, Wang M, . The Highland Health Advocates: a preliminary evaluation of a novel programme addressing the social needs of emergency department patients. Emerg Med J. 2017;34(9):599–605.28642372
19 Luciani-McGillivray I, Cushing J, Klug R, Lee H, Cahill JE. Nurse-Led Call Back Program to Improve Patient Follow-Up With Providers After Discharge From the Emergency Department. Journal of Patient Experience. 2020;7(6):1349–1356.33457586
20 McCormack RP, Hoffman LF, Wall SP, Goldfrank LR. Resource-limited, collaborative pilot intervention for chronically homeless, alcohol-dependent frequent emergency department users. American journal of public health. 2013;103(S2):S221–S224.24148034
21 Nanavati M, Saenz S, Swayne K, Carek P. The Golden Letter: Innovation Collaboration to Reduce Avoidable Hospital Admissions. Journal of the American Board of Family Medicine: JABFM. 2020;33(6):1011–1015.33219081
22 Rinne ST, Resnick K, Wiener RS, Simon SR, Elwy AR. VA provider perspectives on coordinating COPD care across health systems. Journal of general internal medicine. 2019;34(1):37–42.31011970
23 Shuen JA, Wilson MP, Kreshak A, . Telephoned, Texted, or Typed Out: A Randomized Trial of Physician-Patient Communication After Emergency Department Discharge. Journal of Emergency Medicine. 2018;55(4):573–581.
24 Soto GE, Huenefeldt EA, Hengst MN, . Implementation and impact analysis of a transitional care pathway for patients presenting to the emergency department with cardiac-related complaints. BMC Health Services Research. 2018;18(1):672.30165843
25 Tessitore A, Brennan-Cook J. Improving Outpatient Follow-Up Through Innovative Appointment Scheduling at Emergency Department Discharge. Advanced Emergency Nursing Journal. 2021;43(1):71–78.33952879
26 Ayele RA, Lawrence E, McCreight M, . Perspectives of clinicians, staff, and Veterans in transitioning Veterans from non-VA hospitals to primary care in a single VA Healthcare System. Journal of hospital medicine. 2020;15(3):133.
27 Dixon BE, Ofner S, Perkins SM, . Which veterans enroll in a VA health information exchange program? Journal of the American Medical Informatics Association. 2017;24(1):96–105.27274014
28 Dixon BE, Luckhurst C, Haggstrom DA. Leadership Perspectives on Implementing Health Information Exchange: Qualitative Study in a Tertiary Veterans Affairs Medical Center. JMIR medical informatics. 2021;9(2):e19249.33616542
29 Franzosa E, Traylor M, Judon KM, . Perceptions of event notification following discharge to improve geriatric care: qualitative interviews of care team members from a 2-site cluster randomized trial. Journal of the American Medical Informatics Association. 2021;28(8):1728–1735.33997903
30 Martin TR, Gasoyan H, Pirrotta G, Mathew R. A National Survey Assessing Health Information Exchange: Readiness for Changes to Veterans Affairs Access Standards. Perspectives in Health Information Management. 2021;18(3).
31 Olmos-Ochoa TT, Bharath P, Ganz DA, . Staff Perspectives on Primary Care Teams as De Facto “Hubs” for Care Coordination in VA: a Qualitative Study. Journal of General Internal Medicine. 2019;34(1):82–89.
32 Pearson M, Karen B, Burgess MPPM A, Gale MS JA, Coburn PhD AF, Yousefian Hansen M. Health information exchange: a strategy for improving access for rural veterans in the Maine Flex Rural Veterans Health Access. 2016.
33 Altman R, Shapiro JS, Moore T, Kuperman GJ. Notifications of hospital events to outpatient clinicians using health information exchange: a post-implementation survey. Informatics in Primary Care. 2012;20(4):249–255.
34 Atzema CL, Yu B, Ivers NM, . Predictors of obtaining follow-up care in the province of Ontario, Canada, following a new diagnosis of atrial fibrillation, heart failure, and hypertension in the emergency department. CJEM Canadian Journal of Emergency Medical Care. 2018;20(3):377–391.28803593
35 Chang L, Wanner KJ, Kovalsky D, Smith KL, Rhodes KV. “It’s Really Overwhelming”: Patient Perspectives on Care Coordination. Journal of the American Board of Family Medicine: JABFM. 2018;31(5):682–690.30201664
36 Coe AB, Moczygemba LR, Ogbonna KC, Parsons PL, Slattum PW, Mazmanian PE. Low-Income Senior Housing Residents’ Emergency Department Use and Care Transition Problems. Journal of Pharmacy Practice. 2018;31(6):610–616.28990442
37 Cornell SD, Valerio MA, Krause T, Cornell J, Revere L, Taylor BS. Low Adherence to Post Emergency Department Follow-Up Among Hypertensive Patients With Medical Insurance. Journal of Emergency Medicine. 2020;58(2):348–355.
38 Flink M, Ohlen G, Hansagi H, Barach P, Olsson M. Beliefs and experiences can influence patient participation in handover between primary and secondary care--a qualitative study of patient perspectives. BMJ Quality & Safety. 2012;21 Suppl 1:i76–83.
39 Gettel CJ, Hayes K, Shield RR, Guthrie KM, Goldberg EM. Care Transition Decisions After a Fall-related Emergency Department Visit: A Qualitative Study of Patients’ and Caregivers’ Experiences. Academic Emergency Medicine. 2020;27(9):876–886.32053283
40 High PM, Marks K, Robbins V, . State targeted response to the opioid Crisis grants (opioid STR) program: Preliminary findings from two case studies and the national cross-site evaluation. Journal of Substance Abuse Treatment. 2020;108:48–54.31303359
41 Kahan D, Leszcz M, O’Campo P, . Integrating care for frequent users of emergency departments: implementation evaluation of a brief multi-organizational intensive case management intervention. BMC Health Services Research. 2016;16:156.27121969
42 Lockman KA, Lee WH, Sinha R, . Effective acute care handover to GP: optimising the structure to improve discharge documentation. Acute Medicine. 2018;17(2):68–76.29882556
43 Poremski D, Harris DW, Kahan D, . Improving continuity of care for frequent users of emergency departments: service user and provider perspectives. General Hospital Psychiatry. 2016;40:55–59.26906469
44 Richards D, Meshkat N, Chu J, Eva K, Worster A. Emergency department patient compliance with follow-up for outpatient exercise stress testing: a randomized controlled trial. Canadian Journal of Emergency Medicine. 2007;9(6):435–440.18072989
45 Rider AC, Kessler CS, Schwarz WW, . Transition of Care from the Emergency Department to the Outpatient Setting: A Mixed-Methods Analysis. The Western Journal of Emergency Medicine. 2018;19(2):245–253.29560050
46 Rising KL, Padrez KA, O’Brien M, Hollander JE, Carr BG, Shea JA. Return visits to the emergency department: the patient perspective. Annals of Emergency Medicine. 2015;65(4):377–386.e373.25193597
47 Schenhals E, Haidet P, Kass LE. Barriers to compliance with emergency department discharge instructions: lessons learned from patients’ perspectives. Internal & Emergency Medicine. 2019;14(1):133–138.30229524
48 Vieth TL, Rhodes KV. Nonprice barriers to ambulatory care after an emergency department visit. Annals of Emergency Medicine. 2008;51(5):607–613.18436050
49 Walker ER, Fukuda J, McMonigle M, Nguyen J, Druss BG. A Qualitative Study of Barriers and Facilitators to Transitions From the Emergency Department to Outpatient Mental Health Care. Psychiatric Services. 2021:appips202000299.
50 Wexler R, Hefner JL, Sieck C, . Connecting Emergency Department Patients to Primary Care. The Journal of the American Board of Family Medicine. 2015;28(6):722–732.26546647