# APPENDIX F PEER REVIEW DISPOSITION

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | None
2 | 2 | Yes | None
3 | 3 | Yes | None
4 | 4 | Yes | None
5 | 5 | Yes | None
Is there any indication of bias in our synthesis of the evidence?
6 | 1 | No | None
7 | 2 | No | None
8 | 3 | No | None
9 | 4 | No | None
10 | 5 | No | None
Are there any [underlined: published] or [underlined: unpublished] studies that we may have overlooked?
11 | 1 | No | None
12 | 2 | Yes - Perhaps this one: Mi R, Hollander MM, Jones C, DuGoff EH, Caprio TV, Cushman JT, Kind AJ, Lohmeier M, Shah MN. A randomized controlled trial testing the effectiveness of a paramedic-delivered care transitions intervention to reduce emergency department revisits. BMC geriatrics. 2018 Dec;18(1):1–9.29291720 | Thank you. This study is a protocol for a R01. According to ClinicalTrials.gov the study is complete. There are a number of study related publications listed on NIH RePORTER. However, the published preliminary findings focus on feasibility and intervention acceptability, and others did not focus on the intervention. Since we anticipate they plan to publish the findings of their primary outcomes of interest, we added the suggested protocol to our table of studies in progress.
13 | 3 | No | None
14 | 4 | No | None
15 | 5 | No | None
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report.
16 | 1 | PICOTS on page 9 clear. | Thank you.
17 | 1 | Authors may need to review Outcomes for wording “Intermediate outcomes: Over or inappropriate prescribing, duplicate tests or imaging, follow-up by primary care (# days), (?)purpose tests or images ordered in ED are clear.”; In future, I would consider reporting also on HEDIS or VA eTM measures into intermediate outcomes. For instance, instead of just follow up by primary care, would include Follow-Up After Emergency Department Visit for Mental Illness and Follow-Up After Emergency Department Visit for Alcohol and Other Drug Abuse or Dependence by member of SUD or MH. I’m guessing that these are not commonly reported though. | Thank you. We have corrected it to “purpose of tests or images ordered in the ED are clear.”; We agree these are measures worth exploring, and we agree that follow-up for patients with mental health or substance use disorders are an important outcome. Due to the rapid nature of this review, our scope needed to be narrow and the committee prioritized primary care follow up. However, we did identify barriers and facilitators related to a handful of interventions for this population.
18 | 1 | Also, I know that the page size poses a limitation for the supp material. However, I think it might be useful to add a column or some indication in the existing columns for whether or not there was an HIE, where the ED encounter took place (always non-VA?) and where the outpatient setting took place (VA and non-VA). | Thank you. Since this report focused on EDs in the community, we did not include any studies of VA EDs. We have edited our inclusion criteria (PICOTSS) for clarity. The supplement tables indicate Veterans as the population for all studies that applied to VHA settings. We have re-organized the supplemental tables so that they are grouped by population. Similarly, to more easily identify HIE and other interventions, we have consolidated tables so interventions are noted alongside effect.
19 | 1 | I’m guessing that this ESP was performed in response to the high number of ER visits in the community. I wonder what authors think about potential solutions to address care coordination issues based on the evidence review given policy and program implications. | This evidence map was performed to inform a January 2022 State-of-the-Art (SOTA) conference on emergency medicine. One of the main goals of the SOTA is to identify research priorities for VHA, and thus the purpose of this evidence map was to illustrate the characteristics of the body of literature, but not to provide conclusions or recommendations based on the evidence. Further work in this area may arise based on the SOTA conference, including the potential for a systematic review on specific questions in this area of research, which may be able to address potential solutions to the care coordination issues identified in this report.
20 | 2 | Some minor edits suggested in my uploaded draft (below) | Thank you. Please see below.
21 | 2 | Pg. 8, Line 3-4:; they are likely recovering from injuries or acute illness…… | Edited
22 | 2 | Pg. 8, line 30:; More effective | Edited
23 | 2 | Pg. 8, line 31:; Between VA and | Edited to “between VHA and…”
24 | 2 | Pg. 10, line 24 – 25:; Recovering from injuries and acute illness | Edited
25 | 2 | Pg. 10, line 28:; Re-visits | Edited
26 | 2 | Pg. 11, line 16 – 17:; Not sure what this means | Thank you. We have edited this for clarity.
27 | 2 | Pg. 20, line 11:; more effective | Edited
28 | 2 | Pg. 20, line 43 – 46:; Did we decide not to include observational studies? | This statement refers to the included systematic review. This evidence map does include observational studies.
29 | 3 | I thought that the report was concise and straightforward. If anything could be improved, perhaps some clarifying definitions could be given for the bullet points in Figure 1 (e.g., cosmopolitanism, trialability). There was not much substance in the text, while the figures contained more information. I wonder if additional discussion could be brought to the text. | Thank you. We have updated the report to include a list of definitions (Appendix B). With regard to your comment about there being more detail in figures than in the body of the text, the format of this report is an evidence map. As such, the intention of the text is to briefly summarize and/or provide information useful to interpreting the figures.
30 | 4 | This is a complex topic and it was unclear, to me at least, about the focus of this review. It seems to be related to factors that influence outcomes in the ED to outpatient transition. Part of the difficulty is that there is a dearth of published information out there, as was made clear in this review. But perhaps a narrower focus on an analysis of post-ED discharge outcomes and a correlation to post-ED discharge follow-up care might be more gainful. | The key questions and outcomes of interest were developed by the 2022 SOTA conference on emergency medicine community care committee. Due to the broad and complex nature of the topic, the purpose of this evidence map was to illustrate where existing research does and does not exist and to provide a high level summary of the existing literature.
31 | 5 | Title-Include “Implementation”? | We have updated to the title to: Implementation Factors Influencing the Transition from Emergency to Outpatient Care Settings.
32 | 5 | Executive Summary; Should frame this earlier on that these are implementation factors (title) and also the mention of the use of CFIR. Otherwise, someone unfamiliar with CFIR will have no idea what inner/outer setting etc is. Include mention of CFIR in the Background/Methods as well. Otherwise CFIR is not mentioned until page 12. | Thank you. We have added a statement about organization according to CFIR to the executive summary methods and have also added the figure that illustrates CFIR constructs.
33 | 5 | Reporting of CFIR elements-perhaps keep consistent with the order discussed on page 12? Intervention characteristics, outer setting, inner setting, characteristics of individuals, and process factors | We have edited the report for consistency.
34 | 5 | Also, I would use the same terminology in the summary as used later. In the summary you use “implementation processes” vs. “Process factors” | We have edited the report for consistency.
35 | 5 | Figure ES1-is it fair to represent qualitative studies using the same sample size representation as quantitative studies? Virtually all qualitative studies will be the smallest size bubble. However, I would view a qualitative study with 10 participants very different from one in which there were 50-75 interviews. | One key purpose for visualizing data is ease of interpretability. Aligning bubble sizes to different scales based on study design would add a degree of complexity that would hinder interpretation. We knew that the qualitative studies would be interpreted differently, not only within the context of sample size, but also in terms of outcomes effectiveness. Study-level data are provided in the appendices.
36 | 5 | One other issue re. qualitative studies. None of these are mixed methods? Seems like a lot of qualitative studies to have no mixed methods. Plus, looking at the references, at least 4 papers identify themselves as “Mixed Methods” so are these categorized under qualitative or quantitative? | You are correct that some of the included studies were mixed-methods studies. We classified mixed-methods studies based on the component(s) that met inclusion criteria. For example, we categorized Schumacher et al., 2021 “Impact of an emergency department-to-home transitional care intervention on health service use in Medicare beneficiaries: A mixed methods study” which included both an RCT and interviews, as a trial because the qualitative component did not meet inclusion criteria.
37 | 5 | Report; Eligibility criteria; Overall-why not use the accepted “PICOT” abbreviation here? | You are correct that use of PICOT(SS) is well known and widely used in research settings and evidence-based medicine. However, we avoid jargon when possible in order to allow our reports to be accessible to a wide range of readers.
38 | 5 | Intervention-Why must eligible studies involve “the transition from 1 health system to another”? Can’t they be from a VA ED to the same system’s outpatient setting? This seems like an unnecessary exclusion criteria. | The purpose of this report is to inform the transition from community EDs to VHA outpatient care. One of the major barriers is the lack of a shared EHR and there are other barriers simply due to the interaction of healthcare systems and processes. Excluding transitions within the same system increased the likelihood of identifying relevant studies.
39 | 5 | Population-Why not Veterans discharged from VA settings to VHA outpatient care? | Same as above.
40 | 5 | Data Abstraction; Reported Effect p.9 lines 57-8 “whether the reported effect was positive, equal, or negative, and data on barriers and facilitators.” Do you mean beneficial, neutral, and/or detrimental? Not sure what a negative facilitator and/or positive barrier (and vice versa) would mean. | Thank you. We have revised this portion of the sentence to read“…whether the reported intervention effect was positive, equal, or negative, as well as barriers and facilitators to successful ED to outpatient transitions.”
41 | 5 | Figure 5 p.15-the blue for the 2nd blue circle should be more clearly identified (kind of like the orange in Figure 6). Also, this is the first mention of “Community Care” I’d include this earlier and define what this means. Also, the barriers are broken down by setting but then just bulleted for facilitators. | Thank you. We have changed “Community Care” to “Veteran Care in the Community” to avoid confusion. We separated barriers into those that were general or non-setting/population specific and those specific to the VHA and Veterans. No facilitators were Veteran or VHA specific.