# APPENDIX E RESEARCH IN PROGRESS

Status | Study Title | Study Design | Intervention | Information Resources
Completed: October 21, 2016; No publication | Trial of Emergency Department Discharge With Enhanced Transitions of Care Compared to Usual Care (ETOC) | Randomized, parallel assignment | Services provided to assist patients in accessing needed healthcare services after emergency department discharge such as scheduling appointments, finding new doctors, getting medications, or addressing problems with insurance coverage. | NCT02533856
Recruiting | Suicide Prevention Among Recipients of Care (SPARC) | Randomized, parallel assignment | SPI+: Safety Planning Intervention plus structured phone-based follow up; Caring Contacts: Safety Planning Intervention plus Caring Contacts (SP+CC) | NCT04893447
Recruiting | The LEARNING WISDOM Phase II Scale up Project | Randomized, parallel assignment | Behavioral: GEM nurse; Behavioral: pre- and post-hospitalization medication list reconciliation; Behavioral: systematic discharge summaries; Behavioral: medical follow-up appointment; Behavioral: follow-up phone call; Other: Wiki-based Knowledge tools; Other: Telemonitoring service | NCT04093245
Completed; No publication | Paramedic Coached ED Care Transitions to Help Older Adults Maintain Their Health | RCT | Paramedic-delivered ED-to-home Care Transitions Intervention in older adults | NCT02520661