# APPENDIX D EVIDENCE TABLES

## CHARACTERISTICS OF INCLUDED SYSTEMATIC REVIEW

## OUTCOME DATA OF INCLUDED SYSTEMATIC REVIEW

## OUTCOME DATA OF INCLUDED INTERVENTION OUTCOME STUDIES

## BARRIERS AND FACILITATORS DATA

## QUALITY CHARACTERISTICS OF INCLUDED PRIMARY STUDIES