# APPENDIX C EXCLUDED STUDIES

Exclude reasons: 1=Ineligible population, 2=Ineligible intervention, 4=Ineligible outcome, 5=Ineligible timing, 6=Ineligible study design, 7=Ineligible publication type, 8=Outdated or ineligible systematic review, 9=Non-English language10=Study in Included SR, 11=Unable to retrieve FT.

Citation | Exclude Reason
Abraham J, Kannampallil TG, Reddy MC. Peripheral activities during EMR use in emergency care: a case study. AMIA Annual Symposium Proceedings/AMIA Symposium. 2009;2009:1–5.20351811 20351811 | E2
Afilalo M, Lang E, Léger R, . Impact of a standardized communication system on continuity of care between family physicians and the emergency department. Canadian Journal of Emergency Medicine. 2007;9(2):79–86.17391577 | E10
Althaus F, Paroz S, Hugli O, . Effectiveness of interventions targeting frequent users of emergency departments: a systematic review. Ann Emerg Med. 2011;58(1):41–52.e42.21689565 | E8
Arendts G, Bullow K, Etherton-Beer C, . A randomized-controlled trial of a patient-centred intervention in high-risk discharged older patients. European Journal of Emergency Medicine. 2018;25(4):237–241.28027074 | E5
Ballabio C, Bergamaschini L, Mauri S, . A comprehensive evaluation of elderly people discharged from an Emergency Department. Internal & Emergency Medicine. 2008;3(3):245–249.18421427 | E2
Banta-Green CJ, Coffin PO, Merrill JO, . Impacts of an opioid overdose prevention intervention delivered subsequent to acute care. Inj Prev. 2019;25(3):191–198.29436397 | E2
Baren JM, Boudreaux ED, Brenner BE, . Randomized controlled trial of emergency department interventions to improve primary care follow-up for patients with acute asthma. Chest. 2006;129(2):257–265.16478839 | E10
Bell SP, Schnipper JL, Goggins K, . Effect of Pharmacist Counseling Intervention on Health Care Utilization Following Hospital Discharge: A Randomized Control Trial. J Gen Intern Med. 2016;31(5):470–477.26883526 | E10
Biese K, Lamantia M, Shofer F, . A randomized trial exploring the effect of a telephone call follow-up on care plan compliance among older adults discharged home from the emergency department. Acad Emerg Med. 2014;21(2):188–195.24673675 | E10
Bodnar D, Steel P, Sperling J. Discharging low risk chest pain: Is a rapid cardiology follow-up program the answer? A pilot study. Annals of Emergency Medicine. 2014;64(4):S62. | E7
Bond CM, Freiheit EA, Podruzny L, . The emergency to home project: impact of an emergency department care coordinator on hospital admission and emergency department utilization among seniors. Int J Emerg Med. 2014;7:18.24982694 | E1
Bone AE, Evans CJ, Henson LA, Etkind SN, Higginson IJ. Influences on emergency department attendance among frail older people with deteriorating health: a multicentre prospective cohort study. Public Health. 2021;194:4–10.33836318 | E2
Brown MD, Reeves MJ, Meyerson K, Korzeniewski SJ. Randomized trial of a comprehensive asthma education program after an emergency department visit. Ann Allergy Asthma Immunol. 2006;97(1):44–51.16892780 | E10
Chan T, Brennan J, Killeen J, . Impact of Social Services Case Management on Homeless, Frequent Users of Emergency Departments: 577. Academic Emergency Medicine. 2013;20. | E7
Chang J, Chokshi D, Ladapo J. Coordination Across Ambulatory Care: A Comparison of Referrals and Health Information Exchange Across Convenient and Traditional Settings. Journal of Ambulatory Care Management. 2018;41(2):128–137. | E1
Cossette S, Frasure-Smith N, Vadeboncoeur A, McCusker J, Guertin MC. The impact of an emergency department nursing intervention on continuity of care, self-care capacities and psychological symptoms: secondary outcomes of a randomized controlled trial. Int J Nurs Stud. 2015;52(3):666–676.25613830 | E10
Cossette S, Vadeboncoeur A, Frasure-Smith N, McCusker J, Perreault D, Guertin M. Randomized controlled trial of a nursing intervention to reduce emergency department revisits. CJEM. 2013;15:1 23283115 | E10
Currier GW, Fisher SG, Caine ED. Mobile crisis team intervention to enhance linkage of discharged suicidal emergency department patients to outpatient psychiatric services: a randomized controlled trial. Academic Emergency Medicine. 2010;17(1):36–43.20015106 | E10
Davis KA, Miyares MA, Price-Goodnow VS. Optimizing transition of care through the facilitation of a pharmacist-managed deep vein thrombosis treatment program. Journal of Pharmacy Practice. 2013;26(4):438–441.23172896 | E2
Diamant A, Swanson K, Casanova M, Magana R, Boyce E. Improving utilization of medical care and health for chronically homeless adults with housing. Paper presented at: JOURNAL OF GENERAL INTERNAL MEDICINE 2011. | E7
Edgren G, Anderson J, Dolk A, . A case management intervention targeted to reduce healthcare consumption for frequent Emergency Department visitors: results from an adaptive randomized trial. European Journal of Emergency Medicine. 2016;23(5):344.25969342 | E10
Eisenstein EL, Willis JM, Edwards R, . Randomized Trial of Population-Based Clinical Decision Support to Facilitate Care Transitions. Paper presented at: ITCH 2017. | E10
Fockele C, Duber HD, Finegood B, Morse SC, Whiteside L. Improving transitions of care for patients initiated on buprenorphine from the emergency department. Academic Emergency Medicine. 2020;27:S188. | E7
Griffey RT, Shin N, Jones S, . The impact of teach-back on comprehension of discharge instructions and satisfaction among emergency patients with limited health literacy: A randomized, controlled study. J Commun Healthc. 2015;8(1):10–21.26617669 | E10
Grover CA, Close RJ, Villarreal K, Goldman LM. Emergency department frequent user: pilot study of intensive case management to reduce visits and computed tomography. West J Emerg Med. 2010;11(4):336–343.21079705 | E2
Grover CA, Crawford E, Close RJ. The Efficacy of Case Management on Emergency Department Frequent Users: An Eight-Year Observational Study. J Emerg Med. 2016;51(5):595–604.27595372 | E2
Hudon C, Chouinard MC, Lambert M, Diadiou F, Bouliane D, Beaudin J. Key factors of case management interventions for frequent users of healthcare services: a thematic analysis review. BMJ Open. 2017;7(10):e017762. | E8
Jones C, Wood N, Cushman JT, . A novel community paramedicine ed-to-home care transitions program for rural older adults. Academic Emergency Medicine. 2019;26:S90. | E7
Kianfar S, Hundt AS, Hoonakker PLT, . Understanding care transition notifications for chronically ill patients. IISE Transactions on Healthcare Systems Engineering. 2021. | E4
Kolbasovsky A, Reich L, Futterman R, Meyerkopf N. Reducing the number of emergency department visits and costs associated with anxiety: a randomized controlled study. American Journal of Managed Care. 2007;13(2):95–103. | E10
Kumar GS, Klein R. Effectiveness of case management strategies in reducing emergency department visits in frequent user patient populations: a systematic review. J Emerg Med. 2013;44(3):717–729.23200765 | E8
Kwon N, Willis H, Warner L, . An emergency department discharge center to improve patient understanding of discharge instructions and care coordination. Academic Emergency Medicine. 2020;27:S327–S328. | E7
Lang E, Afilalo M, Vandal AC, . Impact of an electronic link between the emergency department and family physicians: a randomized controlled trial. Cmaj. 2006;174(3):313–318.16399880 | E10
Lee JS, Hurley MJ, Carew D, Fisher R, Kiss A, Drummond N. A randomized clinical trial to assess the impact on an emergency response system on anxiety and health care use among older emergency patients after a fall. Acad Emerg Med. 2007;14(4):301–308.17331915 | E10
Lee KH, Davenport L. Can case management interventions reduce the number of emergency department visits by frequent users? Health Care Manag (Frederick). 2006;25(2):155–159.16699330 | E2
McAiney CA, Hillier LM, Paul J, . Improving the seniors’ transition from hospital to the community: a case for intensive geriatric service workers. International Psychogeriatrics. 2017;29(1):149–163.27455883 | E4
McCarty RL, Zarn J, Fenn R, Collins RD. Frequent ED utilizers: A case management program to address patient needs. Nurs Manage. 2015;46(9):24–31; quiz 31-22. | E2
McCormack R, DeMuth M. Feasibility of initiating treatment for alcohol use disorders in the emergency department. Paper presented at: ALCOHOLISM-CLINICAL AND EXPERIMENTAL RESEARCH 2016. | E2
McCormack R, Hoffman L, Goldfrank L. Intervention to Integrate Health and Social Services for Frequent ED Users with Alcohol Use Disorders: 179. Academic Emergency Medicine. 2012;19. | E7
Merritt R, Kulie P, Choudhri T. A randomized controlled trial evaluating a novel approach to post-emergency department follow-up appointment planning. Academic Emergency Medicine. 2017;24:S81–S82. | E7
Neven D, Paulozzi L, Howell D, . A Randomized Controlled Trial of a Citywide Emergency Department Care Coordination Program to Reduce Prescription Opioid Related Emergency Department Visits. J Emerg Med. 2016;51(5):498–507.27624507 | E10
Newman N, Porter B, Hoyt C, . Impact of community pharmacy and home health care transitions of care services on 30-day emergency department revisit rates. Journal of the American Pharmacists Association. 2016;56(3):e92. | E7
Ohuabunwa U, Johnson E, Turner J, Jordan Q, Popoola V, Flacker J. An integrated model of care utilizing community health workers to promote safe transitions of care. Journal of the American Geriatrics Society. 2021;19:19. | E1
Oscalices MIL, Okuno MFP, Lopes M, Campanharo CRV, Batista REA. Discharge guidance and telephone follow-up in the therapeutic adherence of heart failure: randomized clinical trial. Revista Latino-Americana de Enfermagem. 2019;27:e3159.31432915 | E5
Patel PB, Vinson DR. Physician e-mail and telephone contact after emergency department visit improves patient satisfaction: a crossover trial. Ann Emerg Med. 2013;61(6):631–637.23465304 | E10
Pillow MT, Doctor S, Brown S, Carter K, Mulliken R. An Emergency Department-initiated, web-based, multidisciplinary approach to decreasing emergency department visits by the top frequent visitors using patient care plans. J Emerg Med. 2013;44(4):853–860.23102594 | E2
Poremski D, Kahan D, Pauly D, Stergiopoulos V. Challenges in continuity of care: The experience of frequent users of emergency departments in a large metropolitan center in Canada. Annals of the Academy of Medicine Singapore. 2015;44(10):S227. | E11
Rathlev N, Almomen R, Deutsch A, Smithline H, Li H, Visintainer P. Randomized Controlled Trial of Electronic Care Plan Alerts and Resource Utilization by High Frequency Emergency Department Users with Opioid Use Disorder. West J Emerg Med. 2016;17(1):28–34.26823927 | E10
Reinius P, Johansson M, Fjellner A, Werr J, Ohlén G, Edgren G. A telephone-based case-management intervention reduces healthcare utilization for frequent emergency department visitors. Eur J Emerg Med. 2013;20(5):327–334.22960802 | E2
Rinke ML, Dietrich E, Kodeck T, Westcoat K. Operation care: a pilot case management intervention for frequent emergency medical system users. Am J Emerg Med. 2012;30(2):352–357.21269790 | E2
Rosted E, Poulsen I, Hendriksen C, Petersen J, Wagner L. Testing a two step nursing intervention focused on decreasing rehospitalizations and nursing home admission post discharge from acute care. Geriatr Nurs. 2013;34(6):477–485.24041934 | E10
Salerno S, Duckles J, Elliot A, Sellers CA, Christensen T, Shah MN. A qualitative exploration of emergency department revisits by older adults. Academic Emergency Medicine. 2013;20(5):S292–S293. | E7
Sharp B, Singal B, Pulia M, Fowler J, Simmons S. You’ve got mail … and need follow-up: the effect and patient perception of e-mail follow-up reminders after emergency department discharge. Acad Emerg Med. 2015;22(1):47–53.25546255 | E10
Shumway M, Boccellari A, O’Brien K, Okin RL. Cost-effectiveness of clinical case management for ED frequent users: results of a randomized trial. Am J Emerg Med. 2008;26(2):155–164.18272094 | E10
Skinner J, Carter L, Haxton C. Case management of patients who frequently present to a Scottish emergency department. Emerg Med J. 2009;26(2):103–105.19164618 | E2
Soril LJ, Leggett LE, Lorenzetti DL, Noseworthy TW, Clement FM. Reducing frequent visits to the emergency department: a systematic review of interventions. PLoS One. 2015;10(4):e0123660.25874866 | E8
Spivock Smith S, Mahon B, Smith M. Creating a continuum of care: Seniors emergency center. Journal of the American Geriatrics Society. 2011;59:S50. | E7
Stergiopoulos V, Gozdzik A, Cohen A, . The effect of brief case management on emergency department use of frequent users in mental health: Findings of a randomized controlled trial. PLoS One. 2017;12(8):e0182157.28771524 | E10
Suarez Cadenas M, Garcia Brinon MA, Martin-Sanchez FJ. Nurse intervention in the discharge from the emergency department of the frail older patient. Enfermeria Clinica. 2019;29(1):60–61. | E7
Tang R, Gizzi M, Jacobs S, . Implementation of a novel emergency department discharge center. Academic Emergency Medicine. 2021;28(SUPPL 1):S222. | E7
Vaiva G, Vaiva G, Ducrocq F, . Effect of telephone contact on further suicide attempts in patients discharged from an emergency department: randomised controlled study. BMJ (Clinical research ed). 2006;332(7552):1241–1245. | E10
Walsh K. Emergency Department Case Management: the compendium of best practices [Internet] Danvers (MA): HCPro; 2014 [cited 2018 Aug 21]. In:2014. | E7