# APPENDIX A SEARCH STRATEGY

## SYSTEMATIC REVIEWS

Search for current systematic reviews (limited to last 7 years); Date Searched: 09-13-21
A. Bibliographic Databases: | # | Search Statement | Results
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 1] | “Continuity of Patient Care”/ | 20005
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 2] | Patient Handoff/ | 1366
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 3] | Patient Discharge/ | 33694
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 4] | (care adj (transition or transitions or transitioning)).ti,ab. | 1897
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 5] | (care coordination or care coordinating or continuity of care or continuity of patient care or care community).ti,ab. | 13832
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 6] | (discharge plan or discharge plans or discharge planning or discharge instruction or discharge instructions or discharge summary or hospital discharge).ti,ab. | 34424
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 7] | (handover or handoff or handoffs).ti,ab. | 2966
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 8] | (emergency department intervention or ED intervention or ED based intervention).ti,ab. | 126
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 9] | 1 or 2 or 3 or 4 or 5 or 6 or 7 or 8 | 91034
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | 10 | Emergency Medical Services/ | 45177
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | 11 | Emergency Service, Hospital/ | 77091
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | 12 | (emergency medical service$1 or emergency room$1 or emergency department$1 or ED).ti,ab. | 166822
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | 13 | 10 or 11 or 12 | 224209
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | 14 | 9 and 14 | 8336
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 15] | [underlined: (systematic review.ti. or meta-analysis.pt. or meta-analysis.ti. or systematic literature review.ti. or this systematic review.tw. or pooling project.tw. or (systematic review.ti,ab. and review.pt.) or meta synthesis.ti. or meta-analy*.ti. or integrative review.tw. or integrative research review.tw. or rapid review.tw. or umbrella review.tw. or consensus development conference.pt. or practice guideline.pt. or drug class reviews.ti. or cochrane database syst rev.jn. or acp journal club.jn. or health technol assess.jn. or evid rep technol assess summ.jn. or jbi database system rev implement rep.jn. or (clinical guideline and management).tw. or ((evidence based.ti. or evidence-based medicine/ or best practice*.ti. or evidence synthesis.ti,ab.) and (((review.pt. or diseases category/ or behavior.mp.) and behavior mechanisms/) or therapeutics/ or evaluation studies.pt. or validation studies.pt. or guideline.pt. or pmcbook.mp.)) or (((systematic or systematically).tw. or critical.ti,ab. or study selection.tw. or ((predetermined or inclusion) and criteri*).tw. or exclusion criteri*.tw. or main outcome measures.tw. or standard of care.tw. or standards of care.tw.) and ((survey or surveys).ti,ab. or overview*.tw. or review.ti,ab. or reviews.ti,ab. or search*.tw. or handsearch.tw. or analysis.ti. or critique.ti,ab. or appraisal.tw. or (reduction.tw. and (risk/ or risk.tw.) and (death or recurrence).mp.)) and ((literature or articles or publications or publication or bibliography or bibliographies or published).ti,ab. or pooled data.tw. or unpublished.tw. or citation.tw. or citations.tw. or database.ti,ab. or internet.ti,ab. or textbooks.ti,ab. or references.tw. or scales.tw. or papers.tw. or datasets.tw. or trials.ti,ab. or meta-analy*.tw. or (clinical and studies).ti,ab. or treatment outcome/ or treatment outcome.tw. or pmcbook.mp.))) not (letter or newspaper article).pt.] | 474031
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 16] | [underlined: 14 and 15] | 378
MEDLINE: Systematic Reviews; Ovid MEDLINE(R) ALL <1946 to September 10, 2021> | [underlined: 17] | [underlined: limit 16 to english language and yr=“2018-Current”] | 137
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to September 9, 2021 | 1 | ((Continuity of Patient Care) or Patient Handoff or Patient Discharge).kw. | 27
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to September 9, 2021 | 2 | (care adj (transition or transitions or transitioning)).ti,ab. | 1
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to September 9, 2021 | 3 | (care coordination or care coordinating or continuity of care or continuity of patient care or care community).ti,ab. | 14
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to September 9, 2021 | 4 | (discharge plan or discharge plans or discharge planning or discharge instruction or discharge instructions or discharge summary or hospital discharge).ti,ab. | 76
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to September 9, 2021 | 5 | (handover or handoff or handoffs).ti,ab. | 1
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to September 9, 2021 | 6 | (emergency department intervention or ED intervention or ED based intervention).ti,ab. | 0
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to September 9, 2021 | 7 | 1 or 2 or 3 or 4 or 5 or 6 | 103
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to September 9, 2021 | 8 | (Emergency Medical Services or Hospital Emergency Service).kw. | 10
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to September 9, 2021 | 9 | (emergency medical service$1 or emergency room$1 or emergency department$1 or ED).ti,ab. | 142
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to September 9, 2021 | 10 | 8 or 9 | 148
CDSR: Protocols and Reviews; EBM Reviews - Cochrane Database of Systematic Reviews 2005 to September 9, 2021 | 11 | 7 and 10 | 11

Search for current systematic reviews (limited to last 7 years); Date Searched: 09-13-21
B. Non-bibliographic databases | [underlined: Evidence] | [underlined: Results]
AHRQ: evidence reports, technology assessments, U.S Preventative Services Task Force Evidence Synthesis | http://www.ahrq.gov/research/findings/evidence-based-reports/search.html; Search: care coordination; emergency; acute | 0
CADTH | https://www.cadth.ca; Search: care coordination; emergency; acute | 0
ECRI Institute | https://guidelines.ecri.org/; Search: care coordination; emergency; acute | 0
HTA: Health Technology Assessments (UP TO 2016) | http://www.ohsu.edu/xd/education/library/; See Cochrane search above | 0
NHS Evidence | http://www.evidence.nhs.uk/default.aspx; Search: care coordination; emergency; acute | 0
EPPI-Centre | http://eppi.ioe.ac.uk/cms/Default.aspx?tabid=62; Use browser search function [CNTL + F] for keyword search; Search: care coordination; emergency; acute | 0
NLM | http://www.ncbi.nlm.nih.gov/books; Search: care coordination; emergency; acute | 0
VA Products - VATAP, PBM and HSR&D publications | A. http://www.hsrd.research.va.gov/research/default.cfm; B. http://www.research.va.gov/research_topics/; C. https://va.dimensions.ai/discover/publication; Search: care coordination; emergency; acute; VA and Indian Health Services (IHS): Access for American Indian Veterans (https://www.hsrd.research.va.gov/research/abstracts.cfm?Project_ID=2141693892); Measuring and improving specialty care coordination in VA (https://www.hsrd.research.va.gov/research/abstracts.cfm?Project_ID=2141706336); Discharge Information & Support for Patients Receiving Outpatient Care in the ED (https://www.hsrd.research.va.gov/research/abstracts.cfm?Project_ID=2141702004); Care Coordination for High-Risk Patients with Multiple Chronic Conditions (https://www.hsrd.research.va.gov/research/abstracts.cfm?Project_ID=2141706219) | 4

## PRIMARY STUDIES

Search for primary literature; Date searched: 09-13-21
MEDLINE [Ovid MEDLINE(R) ALL <1946 to September 10, 2021>]
# | Search Statement | Results
[underlined: 1] | “Continuity of Patient Care”/ | 20005
[underlined: 2] | Patient Handoff/ | 1366
[underlined: 3] | Patient Discharge/ | 33694
[underlined: 4] | (care adj (transition or transitions or transitioning)).ti,ab. | 1897
[underlined: 5] | (care coordination or care coordinating or continuity of care or continuity of patient care or care community).ti,ab. | 13832
[underlined: 6] | (discharge plan or discharge plans or discharge planning or discharge instruction or discharge instructions or discharge summary or hospital discharge).ti,ab. | 34424
[underlined: 7] | (handover or handoff or handoffs).ti,ab. | 2966
[underlined: 8] | (emergency department intervention or ED intervention or ED based intervention).ti,ab. | 126
[underlined: 9] | 1 or 2 or 3 or 4 or 5 or 6 or 7 or 8 | 91034
10 | Emergency Medical Services/ | 45177
11 | Emergency Service, Hospital/ | 77091
12 | (emergency medical service$1 or emergency room$1 or emergency department$1 or ED).ti,ab. | 166822
13 | Interviews/ or interview*.ti,ab. or experience*.tw. or qualitative.ti,ab. | 1614965
14 | 10 or 11 or 12 | 224209
15 | 9 and 13 and 14 | 1391
16 | Limit 15 to (English language and yr=“1860-2018”) | 1010
17 | 9 and 14 | 8336
18 | limit 17 to (english language and yr="2018 -Current") | 2636
EMBASE
# | Search Statement | Results
1 | ‘clinical handover’/exp | 7968
2 | ‘hospital discharge’/exp | 144318
3 | (care NEAR/1 (transition OR transitions OR transitioning)):ti,ab | 3521
4 | (care NEAR/2 (transition OR transitions OR transitioning)):ti,ab | 7799
5 | ‘care coordination’:ti,ab OR ‘care coordinating’:ti,ab OR ‘continuity of care’:ti,ab OR ‘continuity of patient care’:ti,ab OR ‘care community’:ti,ab | 18870
6 | ‘discharge plan’:ti,ab OR ‘discharge plans’:ti,ab OR ‘discharge planning’:ti,ab OR ‘discharge instruction’:ti,ab OR ‘discharge instructions’:ti,ab OR ‘discharge summary’:ti,ab OR ‘hospital discharge’:ti,ab | 54051
7 | handover:ti,ab OR handoff:ti,ab OR handoffs:ti,ab | 4716
8 | ‘emergency department intervention’:ti,ab OR ‘ed intervention’:ti,ab OR ‘ed based intervention’:ti,ab | 221
9 | #1 OR #2 OR #3 OR #4 OR #5 OR #6 OR #7 OR #8 | 191707
10 | ‘patient transport’/exp | 30726
11 | #9 OR #10 | 218514
12 | ‘emergency health service’/exp | 114855
13 | ‘emergency ward’/exp | 168713
14 | ‘emergency medical service?1’:ti,ab OR ‘emergency room?1’:ti,ab OR ‘emergency department?1’:ti,ab OR ed:ti,ab | 136024
15 | ‘interview’/exp OR interview*:ti,ab OR experience*:ti,ab OR qualitative:ti,ab | 2283647
16 | #12 OR #13 OR #14 | 348778
17 | #9 AND #15 AND #16 | 3022
18 | #9 AND #15 AND #16 AND [english]/lim AND [2019-2021]/py AND [embase]/lim | 825
19 | #9 AND #15 AND #16 AND [english]/lim AND [2019-2021]/py | 939
20 | #9 AND #15 AND #16 AND [english]/lim AND [<1966-2018]/py | 2030
21 | #9 AND #15 AND #16 AND [english]/lim AND [<1966-2018]/py AND [embase]/lim | 1768
22 | #9 AND #15 AND #16 | 3022
23 | #9 AND #15 AND #16 AND [2019-2021]/py | 946
24 | #9 AND #15 AND #16 AND [2019-2021]/py AND [english]/lim | 939
25 | #9 AND #15 AND #16 AND [2019-2021]/py AND [english]/lim AND [embase]/lim | 825

# | Embase Search Statement
1 | “Continuity of Patient Care”/
2 | Patient Handoff/
3 | Patient Discharge/
4 | (care adj (transition or transitions or transitioning)).ti,ab.
5 | (care coordination or care coordinating or continuity of care or continuity of patient care or care community).ti,ab.
6 | (discharge plan or discharge plans or discharge planning or discharge instruction or discharge instructions or discharge summary or hospital discharge).ti,ab.
7 | (handover or handoff or handoffs).ti,ab.
8 | (emergency department intervention or ED intervention or ED based intervention).ti,ab.
9 | 1 or 2 or 3 or 4 or 5 or 6 or 7 or 8
10 | Emergency Medical Services/
11 | Emergency Service, Hospital/
12 | (emergency medical service$1 or emergency room$1 or emergency department$1 or ED).ti,ab.
13 | Interviews/ or interview*.ti,ab. or experience*.tw. or qualitative.ti,ab.
14 | 10 or 11 or 12
15 | 9 and 13 and 14
16 | Limit 15 to (English language and yr=“1860-2018”)
17 | 9 and 14
18 | limit 17 to (english language and yr="2018 -Current")