# REFERENCES

1 Catania C, Muthusamy B, Spitaleri G, Del Signore E, Pennell NA. The new era of immune checkpoint inhibition and target therapy in early-stage non-small cell lung cancer. A review of the literature. Clinical Lung Cancer. 2022;23(2):108–115.34952792
2 Siegel RL, Miller KD, Fuchs HE, Jemal A. Cancer Statistics, 2021. CA: A Cancer Journal for Clinicians. 2021;71(1):7–33. doi:10.3322/caac.21654 33433946
3 Duma N, Santana-Davila R, Molina JR. Non-Small Cell Lung Cancer: Epidemiology, Screening, Diagnosis, and Treatment. Mayo Clinic Proceedings. 2019;94(8):1623–1640.31378236
4 Kocher F, Hilbe W, Seeber A, Longitudinal analysis of 2293 NSCLC patients: A comprehensive study from the TYROL registry. Lung Cancer. 2015;87(2):193–200. doi:10.1016/j.lungcan.2014.12.006 25564398
5 Zhao P, Zhen H, Zhao H, Zhao L, Cao B. Efficacy and safety of adjuvant EGFR-TKIs for resected non-small cell lung cancer: A systematic review and meta-analysis based on randomized control trials. BMC Cancer. 2022;22(1):328.35346117
6 Heiden BT, Eaton DBJ, Chang S- H, Comparison between Veteran and Non-Veteran Populations with Clinical Stage I Non-Small Cell Lung Cancer Undergoing Surgery. Annals of Surgery. 2021. doi:10.1097/sla.0000000000004928
7 Hoggatt KJ, Lehavot K, Krenek M, Schweizer CA, Simpson T. Prevalence of substance misuse among US veterans in the general population. The American Journal on Addictions. 2017;26(4):357–365. doi:10.1111/ajad.12534 28370701
8 Teeters JB, Lancaster CL, Brown DG, Back SE. Substance use disorders in military veterans: Prevalence and treatment challenges. Substance Abuse and Rehabilitation. 2017;8:69–77. doi:10.2147/SAR.S116720 28919834
9 Wei SC, Duffy CR, Allison JP. Fundamental Mechanisms of Immune Checkpoint Blockade Therapy. Cancer Discovery. 2018;8(9):1069–1086. doi:10.1158/2159-8290.Cd-18-0367 30115704
10 He J, Huang Z, Han L, Gong Y, Xie C. Mechanisms and management of 3rd-generation EGFR-TKI resistance in advanced non-small cell lung cancer (Review). Int J Oncol. 2021;59(5):90. doi:10.3892/ijo.2021.5270 34558640
11 Santos GdC, Shepherd FA, Tsao MS. EGFR Mutations and Lung Cancer. Annual Review of Pathology: Mechanisms of Disease. 2011;6(1):49–69. doi:10.1146/annurev-pathol-011110-130206
12 Kawaguchi T, Koh Y, Ando M, Prospective Analysis of Oncogenic Driver Mutations and Environmental Factors: Japan Molecular Epidemiology for Lung Cancer Study. Journal of Clinical Oncology. 2016;34(19):2247–2257. doi:10.1200/jco.2015.64.2322 27161973
13 Shi Y, Au JS- K, Thongprasert S, A Prospective, Molecular Epidemiology Study of EGFR Mutations in Asian Patients with Advanced Non–Small-Cell Lung Cancer of Adenocarcinoma Histology (PIONEER). Journal of Thoracic Oncology. 2014;9(2):154–162. doi:10.1097/JTO.0000000000000033 24419411
14 Xue C, Dong H, Chen Y, Lu X, Zheng S, Cui H. Neoadjuvant Immune Checkpoint Inhibitors in Non-small Cell Lung Cancer. Journal of the College of Physicians & Surgeons - Pakistan. 2022;32(6):779–788.
15 U.S. Food and Drug Administration. FDA approves osimertinib as adjuvant therapy for non-small cell lung cancer with EGFR mutations. Accessed 11/15/2022, https://www.fda.gov/drugs/resources-information-approved-drugs/fda-approves-osimertinib-adjuvant-therapy-non-small-cell-lung-cancer-egfr-mutations
16 U.S. Food and Drug Administration. FDA approves atezolizumab as adjuvant treatment for non-small cell lung cancer. Accessed 11/15/2022, https://www.fda.gov/drugs/resources-information-approved-drugs/fda-approves-atezolizumab-adjuvant-treatment-non-small-cell-lung-cancer
17 U.S. Food and Drug Administration. FDA approves pembrolizumab as adjuvant treatment for non-small cell lung cancer. Accessed 1/30/2023, https://www.fda.gov/drugs/resources-information-approved-drugs/fda-approves-pembrolizumab-adjuvant-treatment-non-small-cell-lung-cancer
18 U.S. Food and Drug Administration. FDA approves neoadjuvant nivolumab and platinum-doublet chemotherapy for early-stage non-small cell lung cancer. Accessed 11/15/2022, https://www.fda.gov/drugs/resources-information-approved-drugs/fda-approves-neoadjuvant-nivolumab-and-platinum-doublet-chemotherapy-early-stage-non-small-cell-lung
19 U.S. Food and Drug Administration. Osimertinib (TAGRISSO). Accessed 1/15/2023, https://www.fda.gov/drugs/resources-information-approved-drugs/osimertinib-tagrisso
20 U.S. Food and Drug Administration. FDA approves osimertinib for first-line treatment of metastatic NSCLC with most common EGFR mutations. Accessed 1/15/2023, https://www.fda.gov/drugs/resources-information-approved-drugs/fda-approves-osimertinib-first-line-treatment-metastatic-nsclc-most-common-egfr-mutations
21 U.S. Food and Drug Administration. FDA approves nivolumab plus ipilimumab for first-line mNSCLC (PD-L1 tumor expression ≥1%). Accessed 11/15/2022, https://www.fda.gov/drugs/resources-information-approved-drugs/fda-approves-nivolumab-plus-ipilimumab-first-line-mnsclc-pd-l1-tumor-expression-1
22 U.S. Food and Drug Administration. Atezolizumab (TECENTRIQ). Accessed 11/15/2022, https://www.fda.gov/drugs/resources-information-approved-drugs/atezolizumab-tecentriq
23 U.S. Food and Drug Administration. FDA expands pembrolizumab indication for first-line treatment of NSCLC (TPS ≥1%). Accessed 11/15/2022, https://www.fda.gov/drugs/fda-expands-pembrolizumab-indication-first-line-treatment-nsclc-tps-1
24 U.S. Food and Drug Administration. FDA approves pembrolizumab in combination with chemotherapy for first-line treatment of metastatic squamous NSCLC. Accessed 11/15/2022, https://www.fda.gov/drugs/fda-approves-pembrolizumab-combination-chemotherapy-first-line-treatment-metastatic-squamous-nsclc
25 Driscoll JJ, Rixe O. Overall Survival: Still the Gold Standard: Why Overall Survival Remains the Definitive End Point in Cancer Clinical Trials. The Cancer Journal. 2009;15(5):401–405. doi:10.1097/PPO.0b013e3181bdc2e0 19826360
26 Mauguen A, Pignon J- P, Burdett S, Surrogate endpoints for overall survival in chemotherapy and radiotherapy trials in operable and locally advanced lung cancer: A re-analysis of meta-analyses of individual patients' data. The Lancet Oncology. 2013;14(7):619–626. doi:10.1016/S1470-2045(13)70158-X 23680111
27 Uprety D. Osimertinib Should Not Yet Be Considered the Standard of Care for EGFR-Mutant NSCLC in the Adjuvant Setting. Journal of Thoracic Oncology. 2021;16(3):371–374. doi:10.1016/j.jtho.2020.12.003 33641721
28 Hashim M, Pfeiffer BM, Bartsch R, Postma M, Heeg B. Do Surrogate Endpoints Better Correlate with Overall Survival in Studies That Did Not Allow for Crossover or Reported Balanced Postprogression Treatments? An Application in Advanced Non–Small Cell Lung Cancer. Value in Health. 2018;21(1):9–17. doi:10.1016/j.jval.2017.07.011 29304946
29 Gyawali B, Hey SP, Kesselheim AS. Evaluating the evidence behind the surrogate measures included in the FDA's table of surrogate endpoints as supporting approval of cancer drugs. EClinicalMedicine. 2020;21:100332. doi:10.1016/j.eclinm.2020.100332 32382717
30 Ren S, Xu A, Lin Y, A narrative review of primary research endpoints of neoadjuvant therapy for lung cancer: Past, present and future. Transl Lung Cancer Res. 2021;10(7):3264–3275. doi:10.21037/tlcr-21-259 34430363
31 Gainor JF. Adjuvant PD-L1 blockade in non-small-cell lung cancer. The Lancet. 2021/10/09/ 2021;398(10308):1281–1283. doi:10.1016/S0140-6736(21)02100-0
32 U.S. Food and Drug Administration. FDA approves atezolizumab for first-line treatment of metastatic NSCLC with high PD-L1 expression. Accessed 11/15/2022, https://www.fda.gov/drugs/resources-information-approved-drugs/fda-approves-atezolizumab-first-line-treatment-metastatic-nsclc-high-pd-l1-expression
33 Gyawali B, Booth C. Disease-Free Survival As a Clinical Trial Endpoint: Does It Matter, and to Whom? American Society of Clinical Oncology. Accessed October 3, 2022. https://dailynews.ascopubs.org/do/disease-free-survival-clinical-trial-endpoint-does-matter-and-whom
34 Gyawali B, de Vries EGE, Dafni U, Biases in study design, implementation, and data analysis that distort the appraisal of clinical benefit and ESMO-Magnitude of Clinical Benefit Scale (ESMO-MCBS) scoring. ESMO Open. 2021;6(3):100117. doi:10.1016/j.esmoop.2021.100117 33887690
35 Zullig LL, Goldstein KM, Sims KJ, Cancer Among Women Treated in the Veterans Affairs Healthcare System. J Womens Health (Larchmt). 2019;28(2):268–275. doi:10.1089/jwh.2018.6936 29920139
36 Zullig LL, Sims KJ, McNeil R, Cancer Incidence Among Patients of the U.S. Veterans Affairs Health Care System: 2010 Update. Military Medicine. 2017;182(7):e1883–e1891. doi:10.7205/milmed-d-16-00371
37 Sterne JAC, Savović J, Page MJ, RoB 2: A revised tool for assessing risk of bias in randomised trials. BMJ. 2019;366:l4898. doi:10.1136/bmj.l4898 31462531
38 Sterne JA, Hernán MA, Reeves BC, ROBINS-I: A tool for assessing risk of bias in non-randomised studies of interventions. BMJ. 2016;355:i4919. doi:10.1136/bmj.i4919 27733354
39 Gebski V, Garès V, Gibbs E, Byth K. Data maturity and follow-up in time-to-event analyses. International Journal of Epidemiology. 2018;47(3):850–859. doi:10.1093/ije/dyy013 29444326
40 Shih WJ. Problems in dealing with missing data and informative censoring in clinical trials. Current Controlled Trials in Cardiovascular Medicine. 2002;3(1):4. doi:10.1186/1468-6708-3-4 11985778
41 Tai T-A, Latimer NR, Benedict Á, Kiss Z, Nikolaou A. Prevalence of Immature Survival Data for Anti-Cancer Drugs Presented to the National Institute for Health and Care Excellence and Impact on Decision Making. Value in Health. 2021;24(4):505–512. doi:10.1016/j.jval.2020.10.016 33840428
42 Dehbi H-M, Royston P, Hackshaw A. Life expectancy difference and life expectancy ratio: two measures of treatment effects in randomised trials with non-proportional hazards. BMJ. 2017;357:j2250. doi:10.1136/bmj.j2250 28546261
43 O’Brien M, Paz-Ares L, Marreaud S, Pembrolizumab versus placebo as adjuvant therapy for completely resected stage IB–IIIA non-small-cell lung cancer (PEARLS/KEYNOTE-091): An interim analysis of a randomised, triple-blind, phase 3 trial. The Lancet Oncology. 2022;23(10):1274–1286. doi:10.1016/S1470-2045(22)00518-6 36108662
44 O'Brien M, Paz-Ares L, Jha N, EORTC-1416-LCG/ETOP 8–15 – PEARLS/KEYNOTE-091 study of pembrolizumab versus placebo for completely resected early-stage non-small cell lung cancer (NSCLC): Outcomes in subgroups related to surgery, disease burden, and adjuvant chemotherapy use. Journal of Clinical Oncology. 2022;40(16_suppl):8512–8512. doi:10.1200/JCO.2022.40.16_suppl.8512
45 Felip E, Altorki N, Zhou C, Adjuvant atezolizumab after adjuvant chemotherapy in resected stage IB-IIIA non-small-cell lung cancer (IMpower010): A randomised, multicentre, open-label, phase 3 trial. Lancet. 2021;398(10308):1344–1357. doi:10.1016/S0140-6736(21)02098-5 34555333
46 Wakelee H, Altorki N, Felip E, PL03.09 IMpower010: Overall Survival Interim Analysis of a Phase III Study of Atezolizumab vs Best Supportive Care in Resected NSCLC. Journal of Thoracic Oncology. 2022;17(9, Supplement):S2. doi:10.1016/j.jtho.2022.07.013
47 Clinical Care Options. IMpower010: Updated Data of Phase III Trial of Adjuvant Atezolizumab vs BSC in Resected Stage IB-IIIA NSCLC After Adjuvant Chemotherapy (CCO Independent Conference Highlights of the IASLC 2022 World Conference on Lung Cancer). 2022. August 16, 2022. https://www.clinicaloptions.com/oncology/conference-coverage/2022/wclc-2022/wclc-highlights/capsule-summary-slidesets/pl03_09
48 Feng S, Wang Y, Cai K, Randomized adjuvant chemotherapy of EGFR-mutated non-small cell lung cancer patients with or without icotinib consolidation therapy. PLoS One. 2015;10(10):e0140794.26474174
49 Li N, Ou W, Ye X, Pemetrexed-carboplatin adjuvant chemotherapy with or without gefitinib in resected stage IIIA-N2 non-small cell lung cancer harbouring EGFR mutations: A randomized, phase II study. Annals of Surgical Oncology. 2014;21(6):2091–6.24585406
50 He J, Su C, Liang W, Icotinib versus chemotherapy as adjuvant treatment for stage II-IIIA EGFR-mutant non-small-cell lung cancer (EVIDENCE): A randomised, open-label, phase 3 trial. Lancet Respir Med. 2021;9(9):1021–1029. doi:10.1016/s2213-2600(21)00134-x 34280355
51 Kelly K, Altorki NK, Eberhardt WE, Adjuvant Erlotinib Versus Placebo in Patients With Stage IB-IIIA Non-Small-Cell Lung Cancer (RADIANT): A Randomized, Double-Blind, Phase III Trial. Journal of Clinical Oncology. 2015;33(34):4007–14.26324372
52 O'Brien MER, Kelly K, Altorki NK, Final follow-up (f/u) results from RADIANT: A randomized double blind phase 3 trial of adjuvant erlotinib (E) versus placebo (P) following complete tumor resection in patients (pts) with stage IB–IIIA EGFR positive (IHC/FISH) non-small cell lung cancer (NSCLC). Journal of Clinical Oncology. 2015;33(15_suppl):7540–7540. doi:10.1200/jco.2015.33.15_suppl.7540
53 Tada H, Mitsudomi T, Misumi T, Randomized Phase III Study of Gefitinib Versus Cisplatin Plus Vinorelbine for Patients With Resected Stage II-IIIA Non-Small-Cell Lung Cancer With Mutation (IMPACT). Journal of Clinical Oncology. 2022;40(3):231–241. doi:10.1200/JCO.21.01729 34726958
54 Wu YL, Tsuboi M, He J, Osimertinib in Resected EGFR-Mutated Non-Small-Cell Lung Cancer. New England Journal of Medicine. 2020;383(18):1711–1723.32955177
55 Wu YL, John T, Grohe C, Postoperative Chemotherapy Use and Outcomes From ADAURA: Osimertinib as Adjuvant Therapy for Resected EGFR-Mutated NSCLC. Journal of Thoracic Oncology. 2022;17(3):423–433. doi:10.1016/j.jtho.2021.10.014 34740861
56 Herbst RS, Wu YL, John T, Adjuvant Osimertinib for Resected EGFR-Mutated Stage IB-IIIA Non-Small-Cell Lung Cancer: Updated Results From the Phase III Randomized ADAURA Trial. J Clin Oncol. 2023:JCO2202186. doi:10.1200/JCO.22.02186
57 Yue D, Xu S, Wang Q, Erlotinib versus vinorelbine plus cisplatin as adjuvant therapy in Chinese patients with stage IIIA EGFR mutation-positive non-small-cell lung cancer (EVAN): A randomised, open-label, phase 2 trial. Lancet Respir Med. Nov 2018;6(11):863–873. doi:10.1016/s2213-2600(18)30277-7 30150014
58 Yue D, Xu S, Wang Q, Updated Overall Survival and Exploratory Analysis From Randomized, Phase II EVAN Study of Erlotinib Versus Vinorelbine Plus Cisplatin Adjuvant Therapy in Stage IIIA Epidermal Growth Factor Receptor+ Non–Small-Cell Lung Cancer. Journal of Clinical Oncology. 2022;40(34):3912–3917. doi:10.1200/JCO.22.00428 36027483
59 Zhong W-Z, Wang Q, Mao W-M, Gefitinib versus vinorelbine plus cisplatin as adjuvant treatment for stage II-IIIA (N1-N2) EGFR-mutant NSCLC (ADJUVANT/CTONG1104): A randomised, open-label, phase 3 study. Lancet Oncology. 2018;19 1077–4114 (Print)(1):139–148. doi:10.1016/S1470-2045(17)30729-5
60 Zhong W-Z, Wang Q, Mao W-M, Gefitinib Versus Vinorelbine Plus Cisplatin as Adjuvant Treatment for Stage II-IIIA (N1-N2) EGFR-Mutant NSCLC: Final Overall Survival Analysis of CTONG1104 Phase III Trial. Journal of Clinical Oncology. 2021;39(7):713–722. doi:10.1200/JCO.20.01820 33332190
61 Liu SY, Bao H, Wang Q, Genomic signatures define three subtypes of EGFR-mutant stage II-III non-small-cell lung cancer with distinct adjuvant therapy outcomes. Nature communications. 2021;12(1):6450.
62 Goss GD, O'Callaghan C, Lorimer I, Gefitinib versus placebo in completely resected non-small-cell lung cancer: results of the NCIC CTG BR19 study. Journal of Clinical Oncology. 2013;31(27):3320–3326. doi:10.1200/JCO.2013.51.1816 23980091
63 Tsuboi M, Kato H, Nagai K, Gefitinib in the adjuvant setting: safety results from a phase III study in patients with completely resected non-small cell lung cancer. Anti-- Cancer Drugs. 2005;16(10):1123–8.
64 Forde PM, Spicer J, Lu S, Neoadjuvant Nivolumab plus Chemotherapy in Resectable Lung Cancer. New England Journal of Medicine. 2022;386(21):1973–1985. doi:10.1056/NEJMoa2202170 35403841
65 Huang Z, Wu Z, Qin Y, Perioperative safety and feasibility outcomes of stage IIIA-N2 non-small cell lung cancer following neoadjuvant immunotherapy or neoadjuvant chemotherapy: a retrospective study. Annals of Translational Medicine. 2021;9(8):685.33987383
66 Xiong L, Lou Y, Bai H, Efficacy of erlotinib as neoadjuvant regimen in EGFR-mutant locally advanced non-small cell lung cancer patients. Journal of International Medical Research. 2020;48(4):300060519887275.31885349
67 Zhao W, Chen T, Ji C, Feasibility of Surgical Resection After Induction Epidermal Growth Factor Receptor-Tyrosine Kinase Inhibitor Therapy for N2 Lung Adenocarcinomas. Annals of Thoracic Surgery. 2021;111(1):290–295.32569671
68 Zhong W, Yang X, Yan H, Phase II study of biomarker-guided neoadjuvant treatment strategy for IIIA-N2 non-small cell lung cancer based on epidermal growth factor receptor mutation status. Journal of Hematology & Oncology. 2015;8(1):1–10.25622682
69 Zhong W-Z, Chen K-N, Chen C, Erlotinib Versus Gemcitabine Plus Cisplatin as Neoadjuvant Treatment of Stage IIIA-N2 -Mutant Non-Small-Cell Lung Cancer (EMERGING-CTONG 1103): A Randomized Phase II Study. Journal of Clinical Oncology. 2019;37(25):2235–2245. doi:10.1200/JCO.19.00075 31194613
70 Provencio M, Serna R, Nadal E, PL03.12 Progression Free Survival and Overall Survival in NADIM II Study. Journal of Thoracic Oncology. 2022;17(9, Supplement):S2-S3. doi:10.1016/j.jtho.2022.07.014
71 Wu YL, Tsuboi M, Grohe C, 296P Osimertinib as adjuvant therapy in patients (pts) with resected EGFR-mutated (EGFRm) stage IB-IIIA non-small cell lung cancer (NSCLC): Updated results from ADAURA. Annals of Oncology. 2022;33:S1548–S1549. doi:10.1016/j.annonc.2022.10.324
72 Rosa K. Updated ADAURA Data Reinforce Adjuvant Osimertinib as SOC for EGFR-Mutated, Stage IB-IIIA NSCLC. OncLive - Clinical Oncology News, Cancer Expert Insights. Accessed January 23, 2023, 2023. https://www.onclive.com/view/updated-adaura-data-reinforce-adjuvant-osimertinib-as-soc-for-egfr-mutated-stage-ib-iiia-nsclc
73 Lei J, Yan X, Zhao J, Tian F, Lu Q, Jiang T. 62MO A randomised, controlled, multicenter phase II trial of camrelizumab combined with albumin-bound paclitaxel and cisplatin as neoadjuvant treatment in locally advanced NSCLC. Annals of Oncology. 2020;31:S1441–S1442.
74 West H, Gyawali B. Why Not Adore ADAURA?—The Trial We Need vs the Trial We Got. JAMA Oncology. 2021;7(5):677–678. doi:10.1001/jamaoncol.2020.6752 33538783
75 Schoenfeld AJ, Yu HA. The Evolving Landscape of Resistance to Osimertinib. Journal of Thoracic Oncology. 2020;15(1):18–21. doi:10.1016/j.jtho.2019.11.005 31864549
76 Pisters K, Kris MG, Gaspar LE, Ismaila N, Therapy ftAS, Panel ARTfSItINGE. Adjuvant Systemic Therapy and Adjuvant Radiation Therapy for Stage I-IIIA Completely Resected Non–Small-Cell Lung Cancer: ASCO Guideline Rapid Recommendation Update. Journal of Clinical Oncology. 2022;40(10):1127–1129. doi:10.1200/jco.22.00051 35167335
77 Sankar K, Bryant AK, Strohbehn GW, Real World Outcomes versus Clinical Trial Results of Durvalumab Maintenance in Veterans with Stage III Non-Small Cell Lung Cancer. Cancers. 2022;14(3):614.35158881
78 Antonia SJ, Villegas A, Daniel D, Durvalumab after Chemoradiotherapy in Stage III Non–Small-Cell Lung Cancer. New England Journal of Medicine. 2017;377(20):1919–1929. doi:10.1056/NEJMoa1709937 28885881
79 Vashistha V, Armstrong J, Winski D, Barriers to Prescribing Targeted Therapies for Patients With NSCLC With Highly Actionable Gene Variants in the Veterans Affairs National Precision Oncology Program. JCO Oncology Practice. 2021;17(7):e1012–e1020. doi:10.1200/OP.20.00703 33780286
80 Williams CD, Alpert N, Redding TS IV, Racial Differences in Treatment and Survival among Veterans and Non-Veterans with Stage I NSCLC: An Evaluation of Veterans Affairs and SEER-Medicare Populations. Cancer Epidemiology, Biomarkers & Prevention. 2020;29(1):112–118. doi:10.1158/1055-9965.Epi-19-0245
81 Ryan BM. Lung cancer health disparities. Carcinogenesis. 2018;39(6):741–751. doi:10.1093/carcin/bgy047 29547922
82 Marandino L, La Salvia A, Sonetto C, Deficiencies in health-related quality-of-life assessment and reporting: A systematic review of oncology randomized phase III trials published between 2012 and 2016. Annals of Oncology. 2018/12/01/ 2018;29(12):2288–2295. doi:10.1093/annonc/mdy449
83 Majem M, Goldman JW, John T, Health-Related Quality of Life Outcomes in Patients with Resected Epidermal Growth Factor Receptor–Mutated Non–Small Cell Lung Cancer Who Received Adjuvant Osimertinib in the Phase III ADAURA Trial. Clinical Cancer Research. 2022;28(11):2286–2296. doi:10.1158/1078-0432.CCR-21-3530 35012927
84 Hwang TJ, Gyawali B. Association between progression-free survival and patients’ quality of life in cancer clinical trials. International Journal of Cancer. 2019;144(7):1746–1751. doi:10.1002/ijc.31957 30374970
85 Das M, Ogale S, Johnson A, EP04.01–017 Cost-Effectiveness of Atezolizumab for Adjuvant Treatment of Patients with Stage II-IIIA PD-L1+ Non-small Cell Lung Cancer. Journal of Thoracic Oncology. 2022;17(9, Supplement):S253. doi:10.1016/j.jtho.2022.07.429
86 Li W, Guo H, Li L, Cui J. Comprehensive Comparison Between Adjuvant Targeted Therapy and Chemotherapy for EGFR-Mutant NSCLC Patients: A Cost-Effectiveness Analysis. Frontiers in Oncology. 2021. doi:10.3389/fonc.2021.619376