# PREFACE

The VA Evidence Synthesis Program (ESP) was established in 2007 to provide timely and accurate syntheses of targeted health care topics of importance to clinicians, managers, and policymakers as they work to improve the health and health care of Veterans. These reports help:

- Develop clinical policies informed by evidence;
- Implement effective services to improve patient outcomes and to support VA clinical practice guidelines and performance measures; and
- Set the direction for future research to address gaps in clinical knowledge.

The program comprises 4 Centers around the US and a Coordinating Center, which are led by VA clinicians and scientists who are recognized leaders in the field of evidence synthesis. The Coordinating Center, located in Portland, Oregon, was created to manage program operations, ensure methodological consistency and quality of products, engage with stakeholders, and address urgent evidence synthesis needs. To ensure responsiveness to VA decision-makers, the ESP is governed by a Steering Committee of health system leadership and researchers. Nominations for ESP reviews are submitted via the program website (https://www.hsrd.research.va.gov/publications/esp/TopicNomination.cfm).