# ACKNOWLEDGMENTS

The present report was developed in response to a request from the VA National Oncology Program Office. The scope was further developed with input from Operational Partners (below) and the ESP Coordinating Center review team. The authors are grateful to Mark Deffebach, MD for providing content expertise during initial review scoping; Kathryn Vela, MLIS for literature searching; Payten Sonnen for data abstraction efforts and editorial and citation management support; David H. Hickam, MD, MPH for feedback on a draft version of this report; and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Michael Kelley, MD
  Executive Director
  National Oncology Program

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix D for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.