# DISCUSSION

In patients with NSCLC who have received 3–4 cycles of platinum-based chemotherapy after complete surgical resection, adjuvant therapy using the ICIs atezolizumab or pembrolizumab likely improves disease-free survival compared with best supportive care or placebo. Results of prespecified exploratory analyses from the pivotal trial of atezolizumab suggest disease-free survival benefit may be limited to patients with PD-L1 ≥ 50%, and that adjuvant atezolizumab may also improve overall survival in this population. Overall survival findings are interim and have not yet been formally tested for statistical significance. The available trial of adjuvant pembrolizumab, PEARLS/KEYNOTE-091, has not reported overall survival results by PD-L1 expression level.

Trials of adjuvant ICIs report contradictory findings about the role of PD-L1 expression levels in disease-free survival outcomes. IMpower010 observed no disease-free survival benefit in patients with PD-L1 < 1%, a small and nonsignificant improvement in patients with PD-L1 between 1–49%, and substantial benefit in patients with PD-L1 ≥ 50%. This pattern is consistent with the understanding that increased PD-L1 expression should correspond to greater efficacy of ICIs. In contrast, PEARLS/KEYNOTE-091 reported a modest (but nonsignificant) improvement in disease-free survival for patients with PD-L1 < 1%, and a larger benefit in patients with PD-L1 between 1–49% than in patients with PD-L1 ≥ 50%. Trial investigators attributed this inconsistency to overperformance of placebo group patients. The trial employed stratified randomization on known prognostic factors (including PD-L1 expression level) and there appeared to be no critical baseline differences between groups, which suggests that better-than-expected outcomes in the placebo group could be due to chance or imbalance in unknown prognostic factors such as molecular biomarkers. Estimates from PEARLS/KEYNOTE-091 also include patients with stage IB disease, which differs from IMpower010 (stage II–IIIA only), and the trials employed different (validated) methods for measuring PD-L1 expression.

In patients with resected, EGFR mutation-positive stage II–IIIA NSCLC, adjuvant therapy with EGFR-TKIs likely improves disease-free survival compared with adjuvant chemotherapy or placebo. The most recent and relevant available trial, ADAURA, found that adjuvant therapy with osimertinib, a third-generation EGFR-TKI, led to substantially improved disease-free survival over placebo. Overall survival data from this trial are immature, limiting conclusions that can be made about overall survival benefits of adjuvant therapy using recent-generation EGFR-TKIs.

A recently published meta-analysis^5^ on the efficacy of adjuvant EGFR-TKIs pooled all included trials and reached similar conclusions with respect to disease-free and overall survival outcomes, and also found that osimertinib was more effective than first-generation EGFR-TKIs at preventing brain metastasis. We did not take the approach of pooling all trials on adjuvant EGFR-TKIs because we concluded that trials were too varied in methodological, treatment, and patient characteristics. Even when synthesizing evidence among relatively similar trials, survival outcomes were notably varied. Inconsistency in results could also be due to differences in EGFR-TKI generation or outcome maturity and reporting, among other factors. An example of the importance of data maturity can be seen in RADIANT, which initially reported a statistically significant and moderate-size disease-free survival benefit of adjuvant erlotinib in the EGFR mutation-positive subsample. With just over a year of additional follow-up, however, the disease-free survival difference between arms was noticeably smaller and no longer significant.

Group differences in disease recurrence, discontinuation because of adverse events, and subsequent therapy observed in several trials of adjuvant EGFR-TKIs could also have contributed to effect variability. When discontinuation because of adverse events mainly occurs in the treatment group, disease-free survival outcomes can be exaggerated in favor of the treatment through informative censoring: patients are censored (because of the toxicity of the trial drug) before experiencing recurrence, while many similar patients in the comparison group remain in the trial (having never been exposed to the trial drug) and ultimately experience recurrence or other eligible outcome events.

A related concern is imbalanced disease recurrence. In ADAURA, for instance, twice as many placebo-group patients experienced recurrence (compared with patients in the osimertinib group), and 85% of these patients discontinued treatment. It has been suggested that differences in recurrence and treatment discontinuation, especially in trials that largely enrolled patients with earlier-stage disease (stage IB or II), may mean that included patients were understaged.^74^ This may be due, in part, to differences in the use of imaging to determine eligibility. For example, ADAURA did not require confirmation of disease stage with imaging studies, meaning that some included patients may have been at a more advanced disease stage that, if known, would have made them ineligible for the trial. Including a substantial number of understaged patients could have exaggerated observed disease-free survival benefits of adjuvant osimertinib.

In ADJUVANT, a mutation was identified that cooccurred with the EGFR mutation and predicted poorer disease-free survival for patients receiving adjuvant targeted therapy (but not chemotherapy). IMPACT and RADIANT did not test for this co-mutation, but it is possible that it was more prevalent among patients in those trials and resulted in poorer disease-free survival in adjuvant EGFR-TKI groups. It has been suggested that the limited disease-free survival benefit seen in IMPACT may be because the trial enrolled fewer patients with an ECOG status of 1 than other comparative-effectiveness trials.^53^ This observation is not supported by subgroup analyses from 2 included trials that found disease-free survival benefits were similar for patients with ECOG status of 0 or 1 (EVIDENCE), or favored patients with a status of 0 (EVAN).

Adverse events associated with ICIs or EGFR-TKIs in the adjuvant setting do not appear be more severe than adjuvant chemotherapy, though the long treatment period of adjuvant therapy with ICIs or EGFR-TKIs may have implications for tolerability, the practicality of long-term treatment adherence, the risk that patients develop resistance to drugs that are important in the treatment of advanced NSCLC, and healthcare costs.^10,74,75^ Moreover, overall survival benefit of adjuvant EGFR-TKIs in mature outcome data has only been shown in EVAN, a comparatively small trial limited to patients with stage III-N2 disease, and overall survival data from recent trials of adjuvant ICIs and EGFR-TKIs have not yet matured. Nonetheless, ICIs and EGFR-TKIs currently approved for adjuvant use likely confer a disease-free survival benefit and appear to be tolerable to most patients. Despite remaining uncertainty about overall survival benefits, adjuvant therapy using these agents could be an option for selected patients with early NSCLC in addition to the current standard of care. For patients with stage II–IIIA disease, this remains conventional adjuvant chemotherapy after surgical resection.^76^

In the neoadjuvant setting, neoadjuvant therapy with the ICI nivolumab plus platinum-based chemotherapy likely improves event-free survival, and may improve overall survival, for patients with resectable NSCLC compared with neoadjuvant chemotherapy alone. Results of prespecified subgroup analyses from the available clinical trial, CheckMate 816, suggest patients with PD-L1 ≥ 50% may experience the largest disease-free survival benefit. Overall survival data from this trial have not yet matured, and the reported hazard ratio for overall survival, though fairly large in magnitude, has not crossed the trial’s adjusted significant threshold. Rates of pathologic complete response were similar regardless of disease stage and were significantly greater than neoadjuvant chemotherapy alone, and treatment benefits were apparent even with limited use of adjuvant chemotherapy.

Adherence to neoadjuvant nivolumab plus chemotherapy was high, and the therapy had a comparable safety profile to neoadjuvant chemotherapy alone. With both therapies, stage 3 or worse adverse events were infrequent and serious adverse events were rare. This is consistent with results of a recent meta-analysis^14^ that synthesized adverse event data mainly from single-group studies of neoadjuvant ICIs, the average rate of grade 3 or worse adverse events was similarly low (15%), and surgical complications and delays after neoadjuvant therapy with ICIs were also rare (10% and 3%, respectively). Patients with tumors bearing EGFR mutations or ALK rearrangements were excluded from the available trial, which may imply the need to test for these alterations prior to treatment.

Finally, we found insufficient evidence to draw conclusions about the efficacy of neoadjuvant ICIs without concurrent neoadjuvant chemotherapy, neoadjuvant therapy using EGFR-TKIs, or combination neoadjuvant-adjuvant therapy with the same ICI or EGFR-TKI.

## REVIEW LIMITATIONS

We did not include evidence from single-group studies in this review. Well-conducted single-group studies can be informative in research areas where few or no RCTs are available, and we recognize that excluding evidence from this type of study may be a limitation of this review.

Visual abstraction of survival proportions was necessary for several included trials. We used tools that improve the accuracy of visually abstracted data, but these survival proportions are likely less accurate than those reported directly in publications. We also visually assessed survival curves for nonproportional hazards, and survival data maturity estimates we calculated are approximate. Judgments made about data immaturity and violations of the proportional hazards assumption involved some degree of subjectivity.

## FUTURE RESEARCH

As noted, inconsistency in trial design, methodology, and patient and treatment characteristics limits the informativeness of available evidence and may contribute to variation in trial findings. The main barrier to synthesis, however, is variability in data analysis and reporting. Included trials of adjuvant therapies used different sample compositions for main analyses (eg, stage IB–IIIA or stage II–IIIA), were missing subgroup analyses (eg, by ECOG status), compared different subgroups (eg, PD-L1 < 1 % versus ≥ 1%, or PD-L1 < 1% versus 1–49% versus ≥ 50%), and finally, differed in whether main or subgroup analyses accounted for important interaction effects (eg, comparing survival in stages IB, II, and IIIA within groups defined by PD-L1 expression or EGFR mutation status). Trials may not have conducted all relevant analyses because of concerns about statistical power, because the importance of certain analyses or moderating factors had not yet become clear, or because key subgroup analyses are being reserved for secondary publications.

Many of these gaps could be addressed by pooling and analyzing patient-level data using an integrative data analysis (IDA) or individual participant data (IPD) meta-analysis approach. Either technique would increase the number of patients in important subgroups and allow for the definitions of key groups (eg, by disease stage and PD-L1 expression level) to be harmonized across studies. Subgroup analyses would gain statistical power, and by combining data from small and large trials, all analyses would be at lower risk of bias from prognostic imbalance (even after randomization, small RCTs can remain imbalanced in the likelihood that patients will respond to treatment or worsen despite treatment). The role of subsequent treatment after recurrence and potential effect modifiers could also be more fully investigated, or adjusted for in key analyses. Often, a barrier to using IDA or IPD methods is unwillingness of trial investigators to share anonymized patient-level data. Advocacy from health system leadership may help to overcome this obstacle.

Clinical data available in an integrated health system like the VA can be useful for assessing the applicability of clinical trial findings to real-world clinical practice. A recent example^77^ of a study with this aim used the VA Informatics and Computing Infrastructure (VINCI) to identify health records of Veterans with unresected stage III NSCLC treated with definitive concurrent chemoradiotherapy followed by adjuvant therapy with an ICI (durvalumab). Progression-free survival and overall survival among these patients was compared to a historical cohort of patients treated with concurrent chemoradiotherapy alone, identified using the VA Cancer Registry System (VACRS). Survival differences were then compared with those observed in the pivotal clinical trial on adjuvant durvalumab in locally advanced, unresectable NSCLC (PACIFIC^78^). The study found that overall survival was improved with the addition of adjuvant durvalumab but not to the extent seen in the PACIFIC trial—findings that, at once, confirm the applicability of trial findings to the VA patient population and identify an efficacy-to-effectiveness gap.

VA health system data also has the potential to inform therapy delivery. In the advanced NSCLC setting, a recent retrospective analysis^79^ of data from the VA Corporate Data Warehouse (CDW) and other VA databases found that only half of patients with evidence of highly targetable mutations had clinical documentation showing their provider was aware of gene sequencing results (available through the VA’s National Precision Oncology Program). This finding does not directly apply to the treatment of resectable NSCLC, but it does underline the importance of ensuring provider awareness of existing resources and how they can be employed in the delivery of emerging therapies. Another recent study^80^ used VA data to examine racial differences in the delivery of first-line treatments for stage I NSCLC. Similar analyses may be useful in the adjuvant setting, where barriers to healthcare access and utilization experienced by minority Veterans^80,81^ could conceivably impact long-term treatment adherence.

Lastly, to maintain a feasible scope, we did not include evidence on the treatment of resectable NSCLC with other targetable features, such as ALK rearrangements. This could be a topic for future evidence reviews, given that at least 1 key trial comparing adjuvant therapy with an ALK-TKI (alectinib) or platinum-based chemotherapy is underway (ALINA; NCT03456076 (https://clinicaltrials.gov/ct2/show/NCT03456076)). In the adjuvant setting, another potential review topic is patient-reported outcomes. Patient-reported outcomes of clinical trials are often published well after survival findings.^34,82^ For example, a recently published analysis^83^ of health-related quality of life data from the ADAURA trial found that quality of life was similar for patients treated with osimertinib or placebo and did not diminish during the treatment period in either group. Quality of life and other patient-reported outcomes from clinical trials can be more severely impacted by assessment and missing data biases than survival outcomes, but generally speaking, trial characteristics and limitations that influence the validity of survival outcomes can also affect patient-reported outcomes.^34^,^82^,^84^ Despite these concerns, synthesizing and critically assessing the evidence that is available on patient-reported outcomes of long-term adjuvant therapy with EGFR-TKIs or ICIs may help to inform clinical decision-making. Evidence on the cost-effectiveness of adjuvant therapies^85,86^ is also developing and may benefit from a future review.

## CONCLUSIONS

ICIs and EGFR-TKIs currently approved for adjuvant use appear to be tolerable to most patients with early NSCLC. Despite some remaining uncertainty about overall survival benefits, adjuvant therapy using these agents could be an option for selected patients with resectable NSCLC in addition to the current standard of care. For patients with stage II–IIIA NSCLC, this remains conventional adjuvant chemotherapy after surgical resection. In the neoadjuvant setting, neoadjuvant therapy with the ICI nivolumab plus platinum-based chemotherapy likely improves event-free survival, and may improve overall survival, for patients with resectable NSCLC compared with neoadjuvant chemotherapy alone. Planned analyses of more mature survival data, particularly in important patient subgroups, may help to clarify remaining questions about the use of ICIs and EGFR-TKIs as adjuvant and neoadjuvant therapies for resectable NSCLC.