# METHODS

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42022354489 (https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42022354489)).

## KEY QUESTIONS

The following key questions were the focus of this review:

Key Question 1 | Among adults with resectable stage I-III NSCLC, what are the survival benefits and harms of adjuvant or neoadjuvant therapy using ICIs or EGFR-TKIs?
Key Question 1a | Do benefits or harms vary by patient characteristics (eg, age, comorbidities), molecular subgroups, or disease stage?

## ELIGIBILITY CRITERIA

Study eligibility criteria are shown in the table below. For studies meeting these criteria, we employed a best-evidence approach to guide final decisions about study and outcome inclusion.

In the most well-developed research area, adjuvant therapy with EGFR-TKIs, we limited eligible studies to randomized controlled trials (RCTs). For adjuvant therapy with ICIs and neoadjuvant therapy with any eligible drug, we included RCTs and other comparative studies meeting eligibility criteria. Survival outcomes were the primary efficacy outcomes of interest in all areas. We prioritized overall and disease-free survival, and when these were not reported, we considered progression-free survival, event-free survival, and pathologic response measures. We did not include evidence from noncomparative studies (eg, single-group studies and case series). RCTs that were stopped early were eligible, but we examined outcome data only if the trial was terminated at a prespecified stopping boundary.

Population | Adults with stage I-III NSCLC who have undergone complete (R0) surgical resection (adjuvant) or with planned surgical resection (neoadjuvant)
Intervention | Adjuvant or neoadjuvant use of ICIs (anti-PD-1 or anti-PD-L1 antibodies including atezolizumab, durvalumab, nivolumab, pembrolizumab, and cemiplimab) or EGFR-TKIs (eg, gefitinib, erlotinib, afatinib, and osimertinib), with or without chemotherapy-based adjuvant therapy
Comparator | Surgical resection without adjuvant or neoadjuvant therapy using ICIs or EGFR-TKIs (eg, chemotherapy-based adjuvant therapy only, placebo intervention only)
Outcomes | Survival, pathologic response, adverse events
Study Design | RCTs, nonrandomized comparison studies; Excluded: Retrospective observational studies, single-group studies, case series, and case studies

## DATA SOURCES AND SEARCHES

To identify eligible studies, a research librarian searched Ovid MEDLINE, CINAHL, ClinicalTrials.gov, as other sources through August 2022 using terms for non-small cell lung cancer, molecularly targeted agent, EGFR tyrosine kinase inhibitor, and immune checkpoint inhibitor (see Appendix A for complete search strategies). Additional citations were identified through consultation with content experts and by hand-searching reference lists, the American Society of Clinical Oncology publications database (https://ascopubs.org/), and public search engines (eg, Google Scholar). Conference abstracts, professional group proceedings, and other non-peer-reviewed publications were included when they reported updated results of eligible studies not available elsewhere. English-language titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by consensus.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Effect information and sample, intervention, and comparator characteristics of included studies were abstracted by 1 investigator, then checked by a second. For survival outcomes, we abstracted hazard ratios (HRs) and 95% confidence intervals (CIs), or p-values for log-rank tests when hazard ratios were unavailable. We also abstracted median survival, proportions of patients surviving up to 5 years, and maturity of survival outcome data (for RCTs only). When survival proportions were not reported but survival curves were available, we visually abstracted proportions using the WebPlotDigitizer platform (https://apps.automeris.io/wpd/). When RCTs did not report survival data maturity, we estimated maturity by dividing the total number of patients with an outcome event at the time of data cutoff by the number of patients randomized.

Study characteristics that could bias findings were assessed using Cochrane risk of bias tools for RCTs^37^ and nonrandomized comparison studies.^38^ Tools were completed independently by 2 investigators, and disagreements were resolved by consensus (see Appendix C). When assessing potential risks of bias, we considered several common sources of bias in clinical trials of cancer therapies and in studies with time-to-event outcomes.^34,39^ These included informative censoring, survival data immaturity, nonproportional hazards, and restriction of crossover in trials of non-novel drugs (drugs already approved for the treatment of more advanced NSCLC).

Informative censoring occurs when patients discontinue treatment and are censored for reasons related to the treatment itself, such as lack of benefit or intolerable side effects.^34,40^ Surrogate survival outcomes (eg, event-free or disease-free survival) may be at risk from informative censoring when there is disproportionate patient withdrawal or discontinuation of the trial drug because of adverse events. Survival data were considered immature when the proportion estimate of maturity was substantially lower than other available trials of the same therapy, when survival curves exhibited a long plateau (regardless of the proportion estimate of maturity), or when a trial explicitly reported that data were immature or made statements to that effect (eg, many or most patients had not yet experienced an outcome event).^41^ Survival curves were visually inspected for the following indicators of nonproportional hazards: curves that substantially diverged from one another, curves that crossed over with extensive follow-up remaining, and curves that separated late in follow-up.^42^ Differences in separation between curves over time was not considered a risk of bias when the largest and smallest separation would correspond to hazard ratios with similar meanings (eg, moderate to large survival benefits of the same therapy).

We considered survival findings from trials of adjuvant therapies using non-novel drugs to be at risk of bias when the trial restricted comparison-group patients from receiving the trial drug or similarly effective treatments for recurring disease. Comparing these patients can result in an apparent benefit of adjuvant therapy that is larger than what would be expected in clinical practice, where treatment of patients with disease recurrence would ordinarily not be delayed.

## SYNTHESIS

Evidence was synthesized narratively by adjuvant and neoadjuvant applications and type of drug. We also investigated potential sources of variation in survival outcomes, including patient characteristics, disease severity, and prior treatment history. Whenever possible, we focused on estimates of survival that used information from the entire follow-up period (eg, hazard ratios from proportional hazards models) rather than survival estimates from single timepoints (eg, median survival or survival proportions). After synthesizing evidence for each outcome, we rated the strength of evidence for survival outcomes based on the methodology and risks of bias of available studies, the consistency and certainty of findings, and the directness of outcomes (whether reported outcomes are relevant to patients and providers).

Consistency in treatment effects occurs when studies conducted in independent settings and patient samples find similar effects. Certainty describes how similar the effects reported by a study, or set of studies, are to the true effect in the patient population of interest. Certainty is evident when the values in a confidence interval―the likeliest true values of an effect―are similar in meaning to the estimated effect. For example, if an estimate of overall survival is accompanied by a wide confidence interval with values that differ in direction and magnitude from the estimate, the true overall survival could be very different from the estimated overall survival. Often this occurs in small samples because it is unclear how representative a few patients are of a larger patient population, and therefore how near the effect in those few patients is to the effect in the population. In this way, certainty also reflects the amount of available evidence, given that larger studies and larger evidence bases tend to yield more precise findings.

Certainty and consistency describe different characteristics of an evidence base. In a group of studies, for instance, studies could be large and provide precise effect estimates. Despite certainty about effects in each study, studies may have been conducted in settings or patients that differed in obvious or unobserved ways, or delivered treatments at different dosages or frequencies. These differences may cause effects to vary in size and direction across studies. When estimates of these effects are synthesized, an overall conclusion about efficacy may not generalize to future studies or to real-world implementation of the treatment. In other words, the effect found by a future study could differ from the overall effect estimate, instead resembling the effect in an existing study that is most closely matched in design, setting, and patient characteristics. If available studies were small and provided imprecise effect estimates, future studies may also find a different effect. In this case, uncertainty about the treatment effect is because existing evidence provides an unclear picture of what the anticipated effect would be.

Strength of evidence was rated using the below criteria. Dashes (—) indicate strength of evidence levels that are unavailable because of the quantity, design, and risks of bias of relevant studies. For this review, directness was not assessed because eligibility criteria required studies to report clinically relevant outcomes.

| High Strength | Moderate Strength | Low Strength
Example Conclusion: | “Adjuvant ICIs improve overall survival” | “Adjuvant ICIs likely improve overall survival” | “Adjuvant ICIs may improve overall survival”
Multiple RCTs with low risk of bias; - with or without -; One or more NRCSs with low or moderate risk of bias | Effect estimates consistent in direction and magnitude; - and -; CIs contain a narrow range of values similar in meaning to effect estimate(s) | Effect estimates consistent in direction only; - and/or -; CIs contain a wider range of values that differ in meaning from effect estimate(s) | Effect estimates differ in direction
One RCT with low risk of bias; - or -; Multiple RCTs with some concerns, or mixed ratings of some concerns and low risk; - with or without -; One or more NRCSs not at critical risk of bias | — | Effect estimates consistent in direction and magnitude; - and -; CIs contain a narrow range of values similar in meaning to effect estimate(s) | Effect estimates differ in direction and/or magnitude; - and/or -; CIs contain a wider range of values that differ in meaning from effect estimate(s)
Multiple NRCSs with low risk of bias | — | Effect estimates consistent in direction and magnitude; - and -; CIs contain a narrow range of values similar in meaning to effect estimate(s) | Effect estimates differ in direction and/or magnitude; - and/or -; CIs contain a wider range of values that differ in meaning from effect estimate(s)
One RCT with some concerns; - or -; Multiple RCTs with high risk of bias, or mixed ratings of some concerns and high risk; - with or without -; One or more NRCSs with any risk of bias rating | — | — | Low-strength evidence regardless of consistency or precision
Multiple NRCSs at moderate risk of bias, or with mixed ratings of low and moderate risk | — | — | Low-strength evidence regardless of consistency or precision
One RCT with high risk of bias | Insufficient; Evidence; (“It is unclear whether neoadjuvant ICIs improve overall survival”)
One or more NRCSs at serious/critical risk of bias, or with mixed ratings of moderate and serious/critical risk | Insufficient; Evidence; (“It is unclear whether neoadjuvant ICIs improve overall survival”)
No available studies | Insufficient; Evidence; (“It is unclear whether neoadjuvant ICIs improve overall survival”)

Abbreviations. NCRS=nonrandomized comparison study; RCT=randomized controlled trial.