# INTRODUCTION

## PURPOSE

The ESP Coordinating Center (ESP CC) is responding to a request from the VA National Oncology Program Office for a synthesis of evidence on the efficacy and safety of immune checkpoint inhibitors (ICIs) and epidermal growth factor receptor-tyrosine kinase inhibitors (EGFR-TKIs) as adjuvant or neoadjuvant therapies for resectable non-small cell lung cancer (NSCLC), which is intended to inform the VHA’s Oncology Clinical Pathways.

## BACKGROUND

NSCLC is the most common form of lung cancer and as many as 80% of patients present with locally advanced or metastatic disease.^1–4^ Patients diagnosed with earlier-stage disease typically undergo surgical resection of the tumor and may also be offered adjuvant therapies.^1,3^ Despite these interventions, NSCLC often recurs, and likelihood of survival falls precipitously with advancing stages of disease.^1,5^ Risk factors for lung cancer are prevalent among Veterans.^6–8^

ICIs and targeted therapies like EGFR-TKIs are important, and relatively recent, advancements in cancer treatment. ICIs block mechanisms that limit immune system activity, in turn increasing the production of tumor-specific immune cells that can attack cancer cells throughout the body.^9^ TKIs interrupt the activity of mutated genes involved in the unchecked cell growth that characterizes cancer.^10,11^ EGFR mutations are not present in all NSCLC.^3,12,13^ Similarly, the quantity of NSCLC cells expressing the regulatory pathways targeted by ICIs (including the programmed death 1 checkpoint and its ligand, PD-L1) varies among patients.^3^ In metastatic NSCLC, survival benefits of ICIs in combination with chemotherapy have been observed across PD-L1 expression levels for patients with NSCLC not driven by EGFR or other mutations, while EGFR-TKIs have shown more promise for patients with mutation-driven advanced NSCLC.^1,3^

Clinical trials are investigating whether benefits of ICIs and EGFR-TKIs seen in metastatic NSCLC extend to early and locally advanced disease.^5,14^ To date, an EGFR-TKI (osimertinib) has been approved for use as an adjuvant monotherapy in patients with certain EGFR mutations, while 2 ICIs (atezolizumab and pembrolizumab) have been approved for adjuvant use following adjuvant platinum-based chemotherapy.^15–17^ Approval of atezolizumab was limited to patients with PD-L1 expression on 1% or more of tumor cells.^16^ Another ICI, nivolumab, was recently approved as a neoadjuvant therapy (ie, prior to surgical resection) in combination with neoadjuvant platinum-doublet chemotherapy.^18^ FDA approval of adjuvant drugs was based on disease-free survival, while efficacy of neoadjuvant nivolumab was demonstrated using event-free survival and pathologic complete response. All 4 drugs had been previously approved for treating advanced NSCLC.^19–24^

Overall survival is generally considered the definitive efficacy outcome for curative-intent cancer therapies,^25–27^ but demonstrating overall survival benefit requires trials to enroll a large number of patients and to follow those patients for a long period.^28^ In some cancers, such as early HER2-positive breast cancer, disease-free survival or other endpoints that are available sooner have been found to be surrogates of overall survival.^29^ Improvement in an endpoint that is a surrogate for overall survival corresponds to similar improvement in overall survival. Surrogacy varies across cancer types and subtypes and by treatment settings, and concerns have been raised about whether endpoints used for FDA approvals are adequate surrogates of overall survival in the context of adjuvant and neoadjuvant therapies for early NSCLC.^27,30–32^

A related concern is that if long-term adjuvant therapy forestalls recurrence of NSCLC—but ultimately does not confer a survival benefit—the therapy may place undue treatment burden and complication risk on patients, particularly when the same drugs are established therapies for advanced NSCLC.^33,34^ From this view, it has been argued that clinical trials of adjuvant therapies must demonstrate overall survival improvement against a control group that had a substantial number of patients cross over to receive the trial drug for disease recurrence.^33^ Otherwise, any apparent overall survival benefit could be the result of comparing patients who received an active treatment to patients for whom standard-of-care treatment (an EGFR-TKI or ICI approved to treat advanced NSCLC) has been delayed.^33,34^

These concerns are relevant to the VA setting, where lung cancers are the second-most frequently diagnosed cancers in Veteran women and men (behind breast and prostate cancers, respectively).^35,36^ To inform decision-making about the treatment of VA patients with resectable NSCLC, we reviewed and critically appraised evidence from clinical trials and other comparative studies on survival benefits and potential harms of neoadjuvant and adjuvant therapy using ICIs and EGFR-TKIs. We also describe considerations and concerns raised by clinicians, researchers, and policymakers about the use of approved agents. This review includes updated results from several key trials that were not available at the time of FDA approvals.