# APPENDIX C QUALITY ASSESSMENT OF INCLUDED STUDIES

## RANDOMIZED CONTROLLED TRIALS (ROB-2)

Trial Name or Author, Year | Risk of Bias from Randomization Process | Risk of Bias from Deviation from Intended Interventions (Assignment) | Risk of Bias from Deviation from Intended Interventions (Adherence) | Risk of Bias from Missing Outcome Data | Risk of Bias in Measurement of Outcome | Risk of Bias in Selection of Reported Result | Overall Bias (Low, Some Concerns, High)
IMpower010^45–47^ | Low; Patients were randomly assigned (1:1) by a permuted-block method with a block size of four to either the atezolizumab arm or best supportive care arm with an interactive voice-web response system.; Randomisation was stratified by sex (female vs male), tumour histology (squamous vs non-squamous), extent of disease (stage IB vs stage II vs stage IIIA), and PD-L1 expression status. Baseline balance. | Low; Used open-label (unblinded) design. Only patients without disease recurrence after CT were enrolled. | Some concerns; (DFS); Low (OS) Substantial differential discontinuation due to adverse events. Similar proportions of patients received non-protocol treatment at recurrence. | Low; Explicit criteria for censoring. | Some concerns; (DFS); Low (OS) Investigators assessing outcomes were aware of treatment assignment. Subgroup analysis of PD-L1 > 1%. | Low; Protocol available. No changes to primary endpoints reported. | Some concerns; (DFS); Low (OS)
Feng 2015^48^ | Some concerns; Does not appear to use stratified randomization. Baseline balance. | Some concerns; Blinding not described. | Some concerns; Blinding not described. Limited deviations. | Low | Some concerns; Investigators assessing outcomes may have been aware of treatment assignment. | Some concerns; Protocol not registered until after enrollment began. Funders had no role in study design, data collection and analysis, decision to publish, or preparation of the manuscript. | Some concerns
CheckMate 816^64^ | Low; Stratified randomization by gender at birth and disease stage. Baseline balance. | Low; Used open-label (unblinded) design but probably limited deviations due to context. | Low; Used open-label (unblinded) design but limited deviations. Most patients in both groups completed treatment, but subsequent treatments were more frequent in CT only group (not considered a risk of bias because progression event counted toward EFS then was subsequently censored). | Low; Explicit criteria for censoring. | Low; Assessment of primary endpoint was blinded. Subgroup analysis by PD-L1 expression level. | Low; Protocol-specified primary outcome (MPR) changed to secondary outcome due to health authority feedback. Rationale provided in supplement, and MPR reported in supplement. | Low
EVIDENCE^50^ | Low; Randomization stratified by EGFR mutation subtype, clinical stage, and resection method. Baseline balance. | Some concerns; Used open-label (unblinded) design. Substantially greater number of pts. in control group did not receive assigned treatment. | Some concerns; Used open-label (unblinded) design | Some concerns; Substantially greater number of pts. in control group missing crucial assessments. | Some concerns; Investigators assessing outcomes were aware of treatment assignment. DFS and OS curves exhibit nonproportionality. | Some concerns; Protocol not available. | Some concerns
Huang 2021^65^ | Some concerns; Randomization method not described, and randomization does not appear to be stratified. Groups did not differ significantly in baseline characteristics but were substantially imbalanced in size. | Some concerns; Blinding not described. | Some concerns; Blinding not described. Deviations not permitted by design. | Low | High; Outcomes were retrospectively collected, suggesting that patients with missingness were not included in the study; investigators assessing outcomes may have been aware of treatment assignment. Did not examine subgroups by PD-L1 expression. | Some concerns; No protocol/registration available. | High
RADIANT^51,52^ | Some concerns; Baseline balance in main groups; in EGFRm+ subgroup more patients in the erlotinib arm having stage IB and more patients in the placebo arm having stage IIIA disease. A smaller proportion of patients receiving erlotinib had lobectomies and received adjuvant chemotherapy. Randomization stratified according to stage, histology, previous adjuvant chemotherapy, smoking status, EGFR status, and country. | Low | Some concerns; (DFS); Low (OS) Many more patients discontinued treatment because of adverse events in treatment arm (not considered an eligible outcome event.) | Low | Some concerns; Investigators assessing outcomes may have been aware of treatment assignment. Violation of proportional hazards for EGFRm+ subgroup. | Low | Some concerns
Li 2014^49^ | Some concerns; Randomization method not described. Randomization was stratified according to gender (male vs female) and smoking history (current or former vs never) only. Baseline balance. | Some concerns; Used open-label (unblinded) design. | Some concerns; Used open-label (unblinded) design. | Low | Some concerns; Investigators assessing outcomes may have been aware of treatment assignment. | Some concerns; No protocol/registration available. | Some concerns
PEARLS/KEYNOTE-091^43,44^ | Low; Triple-blinded design. Randomization was stratified by disease stage (IB vs II vs IIIA), receipt of adjuvant chemotherapy (yes vs no), PD-L1 tumor proportion score (TPS; percentage of tumor cells with membranous PD-L1 staining; <1% vs 1–49% vs ≥50%), and geographical region (Asia vs eastern Europe vs western Europe vs the rest of the world). Baseline balance. | Low; Triple-blinded design. | Some concerns; Triple-blinded design. Median duration and number of treatments were similar in both groups.; Substantial differential discontinuation due to adverse events. Unclear whether there was balance in nonprotocol treatment of recurrences. | Low | Low; Subgroup analyses by EGFR mutation status and PD-L1 expression. | Some concerns; No changes to primary endpoints apparent.; Reporting of subgroup analysis by prior adjuvant therapy at risk of confounding by disease stage. | Some concerns
IMPACT^53^ | Low; Randomization stratified/balanced by institution, stage (II vs III), sex (male vs female), and age. Baseline balance. | Low. | Some concerns; Used open-label (unblinded) design. | Some concerns | Low; Assessment of primary endpoint was blinded. | Low | Some concerns
ADAURA^54,55,71,72^ | Low; Randomization was according to disease stage (IB, II, or IIIA), EGFR mutational status (Ex19del or L858R), and race (Asian or non-Asian). Baseline balance. | Low | Low; Double-blinded. | Low | Low; Some concerns for DFS curves for with adjuvant chemotherapy (all stages) and without CT (stage IIIA) due to nonproportionality. | Low | Low
EVAN^57,58^ | Low; Randomization was stratified by EGFR mutation type (exon 19 vs 21), histology, and smoking status (smoker vs non-smoker). Baseline balance. | Some concerns; Used open-label (unblinded) design. | Some concerns; Used open-label (unblinded) design. | Low | Some concerns Investigators assessing outcomes may have been aware of treatment assignment.; OS curve exhibits nonproportionality. | Low | Some concerns
ADJUVANT^59–61^ | Low; Randomization stratified by lymph node status (N stage [N1 vs N2]) and EGFR mutation subtype (exon 19 deletion vs exon 21 Leu858Arg). Baseline balance. | Low; Used open-label (unblinded) design but probably limited deviations due to context. | Some concerns; Used open-label (unblinded) design. Substantially more control group participants did not receive treatment as allocated. | Low | Some concerns; Individuals with a direct role in the conduct and analysis of the trial did not have access to the randomisation schedule and were masked to treatment assignment until the database was locked.; DFS curve exhibits nonproportionality and converge at 48 months. | Low | Some concerns
EMERGING-CTONG 1103^69^ | Low; Randomization was stratified according to lymph node status (single-station N2 vs multiple station N2), histology, smoking status (never vs former vs current), and sex (male vs female). Baseline balance. | Some concerns; Used open-label (unblinded) design. | Some concerns; Used open-label (unblinded) design. | Low | Some concerns; Investigators assessing outcomes may have been aware of treatment assignment. | Low | Some concerns

Abbreviations. CT=chemotherapy; EGFR=epidermal growth factor receptor; EGFRm+=EGFR mutation positive; PDL=programmed cell death ligand; TKI=tyrosine kinase inhibitor.

## NONRANDOMIZED COMPARISON STUDIES (ROBINS-I)

Author Year | Bias Due to confounding | Selection Bias | Bias in Classification of Interventions | Bias Due to Departures from Intended Interventions | Bias Due to Measurement of Outcomes | Bias Due to Missing Data | Bias in the Selection of Reported Results | Overall Bias (Low, Moderate, Serious, Critical, No Information)
Xiong 2020^66^ | Moderate; Study is unrandomized and provides unadjusted comparisons, but most relevant baseline characteristics appear to be balanced. | No information; Unclear how patients were selected (by investigators, consecutively, etc). | Moderate; Specific edibility criteria provided, but method for determining EGFRm status not described. | Moderate; Appears that all patients completed neoadjuvant treatment as allocated. Groups differed in proportion receiving resection as planned. CT offered to both groups after surgery. | Moderate; Assessors likely unblinded to group status. | Serious; Survival reporting only for those receiving resection (12/15 in treatment, 8/16 in control). | Moderate; No protocol available, but no indication of selective reporting. | Serious
Zhao 2021^67^ | Serious; Study is unrandomized and provides unadjusted comparisons between 2 groups of patients from different sources (a single group trial for tx group and a database for ctrl group). Groups significantly differ in CEA at baseline. | Serious; Selection of patients from database is not described (ie, presumably more than 15 database pts met eligibility criteria, so how was the subset of 15 selected?). | Low; Specific edibility criteria and method for determining EGFRm status described. | Low; Appears that all patients completed neoadjuvant treatment as allocated. CT offered to both groups after surgery. All pts underwent resection. | Serious; Assessors likely unblinded to group status. Unclear if outcome assessment differed for trial (tx) and database (ctrl) pts. | Low; Appears that most or all data were available. | Moderate; Protocol available only for tx group pts, but no indication of selective reporting. | Serious
Zhong 2015^68^ | Moderate; Study is unrandomized and provides unadjusted comparisons, but most relevant baseline characteristics appear to be balanced (with the exception of nonsignificant differences in smoking duration and daily cigarette consumption). | No information; Unclear how patients were selected (by investigators, consecutively, etc). | Moderate; Specific edibility criteria provided, but method for determining EGFRm status not described. | Moderate; Appears that all patients completed neoadjuvant treatment as allocated. Groups differed in proportion receiving resection as planned. | Moderate; Assessors likely unblinded to group status. | Low; Appears that most or all data were available. | Low; Protocol available and no indication of selective reporting. | Moderate

Abbreviations. CEA=carcinoembryonic antigen; CT=chemotherapy; ctrl=control; EGFRm=epidermal growth factor receptor mutation; tx=treatment.