# APPENDIX B EXCLUDED PRIMARY STUDIES

Exclude reasons: 1=Ineligible population, 2=Ineligible intervention, 3=Ineligible comparator, 4=Ineligible outcome, 5=Ineligible timing, 6=Ineligible study design, 7=Ineligible publication type, 8=Outdated or ineligible systematic review (not shown), 9=Non-English language, 10=Unable to locate full text.

Citation | Exclude Reason
Pembrolizumab plus Chemotherapy Doubled Response Rate Over Chemotherapy Alone in NSCLC. Personalized Medicine in Oncology. 2016;5(9):384–384. | E1
Ahn HK, Choi YL, Han JH, Epidermal growth factor receptor mutation and treatment outcome of mediastinoscopic N2 positive non-small cell lung cancer patients treated with neoadjuvant chemoradiotherapy followed by surgery. Lung Cancer. 2013;79(3):300–306.23261144 | E2
Andreano A, Bergamaschi W, Russo AG. Immune checkpoint inhibitors at any treatment line in advanced NSCLC: Real-world overall survival in a large Italian cohort. Lung Cancer. 2021;159:145–152.34340111 | E2
Anonymous. Atezolizumab Extends DFS after NSCLC Relapse. Cancer Discovery. 2021;11(11):OF3. | E7
Anonymous. Neoadjuvant ICI Response, Microbiome Probed in NSCLC. Cancer Discovery. 2021;11(5):OF1. | E10
Aokage K, Miyoshi T, Wakabayashi M, Prognostic influence of epidermal growth factor receptor mutation and radiological ground glass appearance in patients with early-stage lung adenocarcinoma. Lung Cancer. 2021;160:8–16.34365179 | E2
Bai H, Wang Z, Chen K, Influence of chemotherapy on EGFR mutation status among patients with non-small-cell lung cancer. Journal of Clinical Oncology. 2012;30(25):3077–3083.22826274 | E2
Bar J, Urban D, Redinsky I, OA11.01 Neoadjuvant Pembrolizumab for Early Stage Non-Small Cell Lung Cancer. Journal of Thoracic Oncology. 2021;16(10):S865–S866. | E6
Beattie R, Furrer K, Dolan DP, Two centres experience of lung cancer resection in patients with advanced non-small cell lung cancer upon treatment with immune checkpoint inhibitors: safety and clinical outcomes. European Journal of Cardio-Thoracic Surgery. 2021;60(6):1297–1305.34331065 | E6
Besse B, Adam J, Cozic N, 1215O-SC Neoadjuvant atezolizumab (A) for resectable non-small cell lung cancer (NSCLC): Results from the phase II PRINCEPS trial. Annals of Oncology. 2020;31:S794–S795. | E6
Besse B, Mazieres J, Ribassin-Majed L, Pazopanib or placebo in completely resected stage I NSCLC patients: results of the phase II IFCT-0703 trial. Annals of Oncology. 2017;28(5):1078–1083.28327934 | E2
Bott MJ, Yang SC, Park BJ, Initial results of pulmonary resection after neoadjuvant nivolumab in patients with resectable non-small cell lung cancer. Journal of Thoracic & Cardiovascular Surgery. 2019;158(1):269–276.30718052 | E6
Bryant AK, Sankar K, Strohbehn GW, Prognostic and Predictive Role of PD-L1 Expression in Stage III Non-small Cell Lung Cancer Treated With Definitive Chemoradiation and Adjuvant Durvalumab. International Journal of Radiation Oncology, Biology, Physics. 2022;113(4):752–758.35450753 | E1
Bryant AK, Sankar K, Strohbehn GW, Timing of Adjuvant Durvalumab Initiation Is Not Associated With Outcomes in Stage III Non-small Cell Lung Cancer. International Journal of Radiation Oncology, Biology, Physics. 2022;113(1):60–65.35115216 | E1
Bryant AK, Sankar K, Zhao L, De-escalating adjuvant durvalumab treatment duration in stage III non-small cell lung cancer. European Journal of Cancer. 2022;171:55–63.35704975 | E1
Carbone D, Lee J, Kris M, OA06. 06 Clinical/biomarker data for neoadjuvant atezolizumab in resectable stage IB-IIIB NSCLC: primary analysis in the LCMC3 study. Journal of Thoracic Oncology. 2021;16(3):S115-S116. | E6
Cascone T, William WN, Jr., Weissferdt A, Neoadjuvant nivolumab or nivolumab plus ipilimumab in operable non-small cell lung cancer: the phase 2 randomized NEOSTAR trial. Nature Medicine. 2021;27(3):504–514. | E2
Chaft JE, Hellmann MD, Velez MJ, Travis WD, Rusch VW. Initial Experience With Lung Cancer Resection After Treatment With T-Cell Checkpoint Inhibitors. Annals of Thoracic Surgery. 2017;104(3):e217-e218.28838509 | E6
Chang AY. The role of gefitinib in the management of Asian patients with non-small cell lung cancer. Expert Opinion on Investigational Drugs. 2008;17(3):401–411.18321238 | E2
Chen T, Ning J, Campisi A, Neoadjuvant PD-1 Inhibitors and Chemotherapy for Locally Advanced NSCLC: A Retrospective Study. Annals of Thoracic Surgery. 2022;113(3):993–999.33781737 | E6
Chen Y, Yan B, Xu F, Neoadjuvant chemoimmunotherapy in resectable stage IIIA/IIIB non-small cell lung cancer. Transl Lung Cancer Res. 2021;10(5):2193–2204.34164269 | E6
Chuang JC, Neal JW, Niu XM, Wakelee HA. Adjuvant therapy for EGFR mutant and ALK positive NSCLC: Current data and future prospects. Lung Cancer. 2015;90(1):1–7.26275476 | E7
Chung KP, Shih JY, Yu CJ. Favorable response to gefitinib treatment of lung adenocarcinoma with coexisting germline and somatic epidermal growth factor receptor mutations. Journal of Clinical Oncology. 2010;28(34):e701–703.20823418 | E6
Costa DB, Kobayashi S, Tenen DG, Huberman MS. Pooled analysis of the prospective trials of gefitinib monotherapy for EGFR-mutant non-small cell lung cancers. Lung Cancer. 2007;58(1):95–103.17610986 | E2
D'Angelo SP, Janjigian YY, Ahye N, Distinct clinical course of EGFR-mutant resected lung cancers: results of testing of 1118 surgical specimens and effects of adjuvant gefitinib and erlotinib. Journal of Thoracic Oncology: Official Publication of the International Association for the Study of Lung Cancer. 2012;7(12):1815–1822.23154553 | E6
Darrason M, Chatelain E, Ranchon F, Gervaise C, Duruisseaux M, Couraud S. Do systemic treatments delivered after Nivolumab result in better outcomes? A bicentric case-control study. Respiratory Medical Research. 2020;77:100–105. | E1
Dickhoff C, Senan S, Schneiders FL, Ipilimumab plus nivolumab and chemoradiotherapy followed by surgery in patients with resectable and borderline resectable T3–4N0–1 non-small cell lung cancer: the INCREASE trial. BMC Cancer. 2020;20(1):764.32795284 | E7
Duan H, Wang T, Luo Z, Neoadjuvant programmed cell death protein 1 inhibitors combined with chemotherapy in resectable non-small cell lung cancer: an open-label, multicenter, single-arm study. Translational Lung Cancer Research. 2021;10(2):1020–1028.33718040 | E6
Eichhorn F, Klotz LV, Kriegsmann M, Neoadjuvant anti-programmed death-1 immunotherapy by pembrolizumab in resectable non-small cell lung cancer: First clinical experience. Lung Cancer. 2021;153:150–157.33529989 | E6
Eide IJZ, Nilssen Y, Lund-Iversen M, Brustugun OT. Factors affecting outcome in resected EGFR-mutated lung cancer. Acta Oncologica. 2022;61(6):749–756.35473448 | E2
El Husseini K, Piton N, De Marchi M, Lung Cancer Surgery after Treatment with Anti-PD1/PD-L1 Immunotherapy for Non-Small-Cell Lung Cancer: A Case— Cohort Study. Cancers. 2021;13(19):4915.34638399 | E6
Faehling M, Witte H, Sebastian M, Real-world multicentre analysis of neoadjuvant immunotherapy and chemotherapy in localized or oligometastatic non-small cell lung cancer (KOMPASSneoOP). Therapeutic Advances in Medical Oncology. 2022;14:17588359221085333.35356258 | E6
Feng Y, Sun W, Zhang J, Neoadjuvant PD-1 inhibitor combines with chemotherapy versus neoadjuvant chemotherapy in resectable squamous cell carcinoma of the lung. Thoracic Cancer. 2022;13(3):442–452.34913597 | E6
Forde PM, Chaft JE, Smith KN, Neoadjuvant PD-1 Blockade in Resectable Lung Cancer. New England Journal of Medicine. 2018;378(21):1976–1986.29658848 | E6
Forde PM, Reiss KA, Zeidan AM, Brahmer JR. What lies within: novel strategies in immunotherapy for non-small cell lung cancer. Oncologist. 2013;18(11):1203–1213.24105749 | E7
Fuerst ML. Higher Doses of Second-Line Nivolumab Safe & Effective for Advanced NSCLC. Oncology Times. 2019;41(8):30–30. | E7
Gao S, Li N, Gao S, Neoadjuvant PD-1 inhibitor (Sintilimab) in NSCLC. Journal of Thoracic Oncology: Official Publication of the International Association for the Study of Lung Cancer. 2020;15(5):816–826.32036071 | E6
Ghisoni E, Wicky A, Bouchaab H, Late-onset and long-lasting immune-related adverse events from immune checkpoint-inhibitors: An overlooked aspect in immunotherapy. European Journal of Cancer. 2021;149:153–164.33865201 | E1
Goodwin PM. Early Lung Cancer Responds to Neoadjuvant Nivolumab. Oncology Times. 2016;38(25):32–32. | E7
Gupta R, Zaid S, Sayed A, Atezolizumab Induced Myocarditis on a Background of Cardiac Amyloidosis. American Journal of Therapeutics. 2019;26(6):e795-e797.31045879 | E6
Haratani K, Hayashi H, Chiba Y, Association of Immune-Related Adverse Events With Nivolumab Efficacy in Non-Small-Cell Lung Cancer. JAMA Oncology. 2018;4(3):374–378.28975219 | E1
He Q, Liu J, Cai X, Comparison of first-generation EGFR-TKIs (gefitinib, erlotinib, and icotinib) as adjuvant therapy in resected NSCLC patients with sensitive EGFR mutations. Translational Lung Cancer Research. 2021;10(11):4120–4129.35004243 | E6
Hill A, Gong J, Wilczynski S, Mirza R, Erhunmwunsee L, Salgia R. Complete Pathologic Response When Adding Pembrolizumab to Neoadjuvant Chemotherapy in Stage IIIA Non-Small-Cell Lung Cancer. Journal of oncology practice/American Society of Clinical Oncology. 2018;14(9):569–571. | E6
Hong MH, Ahn B, Kim HR, FP03.02 Interim Analysis of Neoadjuvant Chemoradiotherapy and Durvalumab for Potentially Resectable Stage III Non-Small Cell Lung Cancer (NSCLC). Journal of Thoracic Oncology. 2021;16(3):S194-S195. | E6
Hu Y, Ren S, Yang L, Osimertinib as Neoadjuvant Therapy for Resectable Non-Small Cell Lung Cancer: A Case Series. Frontiers in Pharmacology. 2022;13:912153.35571073 | E6
Issa M, Tang J, Guo Y, Risk factors and predictors of immune-related adverse events: implications for patients with non-small cell lung cancer. Expert Review of Anticancer Therapy. 2022;22(8):861–874.35786142 | E7
Janjigian YY, Park BJ, Zakowski MF, Impact on disease-free survival of adjuvant erlotinib or gefitinib in patients with resected lung adenocarcinomas that harbor EGFR mutations. Journal of Thoracic Oncology: Official Publication of the International Association for the Study of Lung Cancer. 2011;6(3):569–575.21150674 | E6
Joshi K, Muhith A, Obeid M, Safety monitoring of two and four-weekly adjuvant durvalumab for patients with stage III NSCLC: implications for the COVID-19 pandemic and beyond. Lung Cancer. 2021;156:147–150.33965281 | E1
Kappers I, Klomp HM, Burgers JA, Van Zandwijk N, Haas RL, van Pel R. Neoadjuvant (induction) erlotinib response in stage IIIA non-small-cell lung cancer. Journal of Clinical Oncology. 2008;26(25):4205–4207.18757336 | E7
Kashiwabara K, Fujii S, Tsumura S, Sakamoto K, Semba H. Additional bevacizumab in EGFR-mutant lung adenocarcinoma patients who had oligo-progression after the failure of EGFR-TKI: A single-institute retrospective study. Cancer Treatment And Research Communications. 2020;22:100163.31675534 | E1
Kim Y, Saraf A, Iii DMM, Quantitative Evaluation of Normal Lung Density Changes in Non-Small Cell Lung Cancer Patients Treated With Radiotherapy and PD-1 Immune Checkpoint Inhibitors. International Journal of Radiation Oncology, Biology, Physics. 2021;111(3):e131-e131. | E1
King W. Adjuvant Treatment with Osimertinib Is Highly Effective in EGFR-Mutated Earlier-Stage NSCLC. Oncology Pharmacist. 2020;13(5):15–15. | E7
Koch A, Sponholz S, Trainer S, Pulmonary Resection after Radiosurgery and Neoadjuvant Immunochemotherapy for NSCLC Patients with Synchronous Brain Metastasis-A Case Series of Three Patients. Current Oncology. 2022;29(4):2225–2239.35448155 | E1
Koch A, Sponholz S, Trainer S, Pulmonary Resection after Radiosurgery and Neoadjuvant Immunochemotherapy for NSCLC Patients with Synchronous Brain Metastasis—A Case Series of Three Patients. Current Oncology. 2022;29(4):2225–2239.35448155 | Duplicate
Kozuki T, Fujimoto N, Ueoka H, Complexity in the treatment of pulmonary large cell neuroendocrine carcinoma. Journal of Cancer Research & Clinical Oncology. 2005;131(3):147–151.15538626 | E1
Landman Y, Jacobi O, Kurman N, Durvalumab after concurrent chemotherapy and high-dose radiotherapy for locally advanced non-small cell lung cancer. Oncoimmunology. 2021;10(1):1959979.34408921 | E1
Lara-Guerra H, Chung CT, Schwock J, Histopathological and immunohistochemical features associated with clinical response to neoadjuvant gefitinib therapy in early stage non-small cell lung cancer. Lung Cancer. 2012;76(2):235–241.22112291 | E4
Lee J, Chaft J, Nicholas A, PS01. 05 surgical and clinical outcomes with neoadjuvant atezolizumab in resectable stage IB–IIIB NSCLC: LCMC3 trial primary analysis. Journal of Thoracic Oncology. 2021;16(3):S59-S61. | E6
Lee JM, Tsuboi M, Brunelli A. Surgical Perspective on Neoadjuvant Immunotherapy in Non-Small Cell Lung Cancer. Annals of Thoracic Surgery. 2021;30:30. | E7
Lei J, Yan X, Zhao J, Tian F, Lu Q, Jiang T. 62mo a randomised, controlled, multicenter phase ii trial of camrelizumab combined with albumin-bound paclitaxel and cisplatin as neoadjuvant treatment in locally advanced nsclc. Annals of Oncology. 2020;31:S1441-S1442 | E7
Li C, Lu H. Adenosquamous carcinoma of the lung. OncoTargets and therapy. 2018;11:4829–4835.30147334 | E7
Li Q, Ma L, Qiu B, Benefit from Adjuvant TKIs Versus TKIs Plus Chemotherapy in EGFR-Mutant Stage III-pN2 Lung Adenocarcinoma. Current Oncology. 2021;28(2):1424–1436.33916930 | E6
Liu YT, Gao YS, Mao YS, [The outcome and safety of neoadjuvant PD-1 blockade plus chemotherapy in stage II ~ II non-small cell lung cancer]. Zhonghua Zhong Liu Za Zhi. 2020;42(6):480–485.32575944 | E9
Liu Z, Gao Z, Zhang M, Real-World Effectiveness and Prognostic Factors Analysis of Stages I-III Non-Small Cell Lung Cancer Following Neoadjuvant Chemo-Immunotherapy or Neoadjuvant Chemotherapy. Annals of Thoracic & Cardiovascular Surgery. 2022;28(2):111–120.34776459 | E6
Lourdes LS, Jalal SI, Hanna N. Adjuvant Epidermal Growth Factor Receptor Inhibitors in Non-Small Cell Lung Cancer. Oncologist. 2015;20(9):975–978.26268739 | E7
Lücke E, Ganzert C, Föllner S, [Operability and Pathological Response of Non-Small Cell Lung Cancer (NSCLC) after Neoadjuvant Therapy with Immune Checkpoint Inhibition]. Pneumologie. 2020;74(11):766–772.32820489 | E9
Lv C, An C, Feng Q, A Retrospective Study of Stage I to IIIa Lung Adenocarcinoma After Resection: What Is the Optimal Adjuvant Modality for Patients With an EGFR Mutation? Clinical Lung Cancer. 2015;16(6):e173–181.25958850 | E6
Mazzoni F, Petreni P, Perna M, Afatinib with subsequent surgery in stage III NSCLC with EGFR mutation: Lessons learned from two clinical experiences. Tumori. 2018;104(6):NP5-NP9.29895214 | E6
Melosky B, Cheema P, Juergens RA, The dawn of a new era, adjuvant EGFR inhibition in resected non-small cell lung cancer. Therapeutic Advances in Medical Oncology. 2021;13:17588359211056306.34804219 | E7
Miyamaru S, Murakami D, Nishimoto K, Treatment Outcomes of Pulmonary Metastases from Head and Neck Squamous Cell Carcinoma. Acta Medica Okayama. 2021;75(1):31–37.33649611 | E1
Naqash AR, Stroud CRG, Butt MU, Co-relation of overall survival with peripheral blood-based inflammatory biomarkers in advanced stage non-small cell lung cancer treated with anti-programmed cell death-1 therapy: results from a single institutional database. Acta Oncologica. 2018;57(6):867–872.29241410 | E1
Nieder C, Aanes SG, Haukland EC. Survival and Early Death Within Three Months from the Start of Immune Checkpoint Inhibitors in Patients With Different Types of Cancer. Anticancer Research. 2022;42(6):3061–3066.35641252 | E1
Ning Y, Bao M, Yan X, Xie D, Jiang G. Surgery for advanced non-small cell lung cancer patient after epidermal growth factor receptor tyrosine kinase inhibitor neoadjuvant therapy. Annals of Translational Medicine. 2018;6(20):407.30498734 | E6
Nishida T, Saito Y, Fukai R. Neoadjuvant gefitinib therapy: a potential standard therapy for non-small cell lung cancer. Journal of Thoracic Disease. 2022;14(4):799–801.35572864 | E7
Ohri N, Halmos B, Bodner WR, Who Benefits the Most From Adjuvant Durvalumab After Chemoradiotherapy for Non-small Cell Lung Cancer? An Exploratory Analysis. Practical Radiation Oncology. 2021;11(2):e172-e179.33127337 | E1
Owada-Ozaki Y, Muto S, Takagi H, Prognostic Impact of Tumor Mutation Burden in Patients With Completely Resected Non-Small Cell Lung Cancer: Brief Report. Journal of Thoracic Oncology. 2018;13(8):1217–1221.29654927 | E2
Parikh AB, Hammons L, Gomez JE. Neoadjuvant Tyrosine Kinase Inhibition in Locally-advanced Non-small Cell Lung Cancer: Two Cases and a Brief Literature Review. Anticancer Research. 2019;39(2):897–902.30711973 | E1
Pasello G, Lorenzi M, Pretelli G, Diagnostic-Therapeutic Pathway and Outcomes of Early Stage NSCLC: a Focus on EGFR Testing in the Real-World. Frontiers in Oncology. 2022;12:909064.35847912 | E1
Pennell NA. Adjuvant Targeted Therapy for Patients With Epidermal Growth Factor Receptor-Mutant Lung Cancer. JAMA Oncology. 2021;7(5):679–680.33538781 | E7
Pennell NA, Neal JW, Chaft JE, SELECT: A Phase II Trial of Adjuvant Erlotinib in Patients With Resected Epidermal Growth Factor Receptor-Mutant Non-Small-Cell Lung Cancer. Journal of Clinical Oncology. 2019;37(2):97–104.30444685 | E6
Pennock MM, Halmos B, Iii WRB, Cheng H, Gucalp R, Ohri N. Predictors of Early Durvalumab Discontinuation After Chemoradiotherapy for Non-Small Cell Lung Cancer. International Journal of Radiation Oncology, Biology, Physics. 2021;111(3):e448-e449. | E1
Planchard D. Adjuvant Osimertinib in -Mutated Non-Small-Cell Lung Cancer. New England Journal of Medicine. 2020;383(18):1780–1782.33113300 | E7
Provencio M, Serna-Blasco R, Nadal E, Overall Survival and Biomarker Analysis of Neoadjuvant Nivolumab Plus Chemotherapy in Operable Stage IIIA Non-Small-Cell Lung Cancer (NADIM phase II trial). Journal of Clinical Oncology. 2022:JCO2102660. | E6
Provencio M, Nadal E, Insa A, Neoadjuvant chemotherapy and nivolumab in resectable non-small-cell lung cancer (NADIM): an open-label, multicentre, singlearm, phase 2 trial. Lancet Oncology. 2020;21(11):1413–1422.32979984 | E6
Ready N, Tong B, Clarke J, P2.04-89 Neoadjuvant Pembrolizumab in Early Stage Non-Small Cell Lung Cancer (NSCLC): Toxicity, Efficacy, and Surgical Outcomes. Journal of Thoracic Oncology. 2019;14:S745-S745. | E4
Reuss JE, Anagnostou V, Cottrell TR, Neoadjuvant nivolumab plus ipilimumab in resectable non-small cell lung cancer. Journal for Immunotherapy of Cancer. 2020;8(2):09. | E7
Rizvi NA, Rusch V, Pao W, Molecular characteristics predict clinical outcomes: prospective trial correlating response to the EGFR tyrosine kinase inhibitor gefitinib with the presence of sensitizing mutations in the tyrosine binding domain of the EGFR gene. Clinical Cancer Research. 2011;17(10):3500–3506.21558399 | E6
Romero Roman A, Campo-Canaveral de la Cruz JL, Macia I, Outcomes of surgical resection after neoadjuvant chemoimmunotherapy in locally advanced stage IIIA non-small-cell lung cancer. European Journal of Cardio-Thoracic Surgery. 2021;60(1):81–88.33661301 | E2
Rosell R, Ito M. Neoadjuvant atezolizumab plus chemotherapy in resectable non-small-cell lung cancer. Lancet Oncology. 2020;21(6):736–738.32386569 | E7
Rosell R, Karachaliou N. Adjuvant therapy for resected EGFR-mutant non-smallcell lung cancer. Lancet Oncology. 2018;19(3):e126.29508751 | E7
Rothschild SI, Zippelius A, Eboulet EI, SAKK 16/14: Durvalumab in Addition to Neoadjuvant Chemotherapy in Patients With Stage IIIA(N2) Non-Small-Cell Lung Cancer-A Multicenter Single-Arm Phase II Trial. Journal of Clinical Oncology. 2021;39(26):2872–2880.34251873 | E6
Saad A, Goldstein J, Appel S, Chemoradiation followed by adjuvant durvalumab in stage III non-small cell lung cancer: Real-world comparison of treatment outcomes to historical controls treated with chemoradiation alone. Thoracic Cancer. 2022;13(12):1763–1771.35538909 | E1
Saisho S, Yasuda K, Maeda A, Post-recurrence survival of patients with non-small-cell lung cancer after curative resection with or without induction/adjuvant chemotherapy. Interactive Cardiovascular & Thoracic Surgery. 2013;16(2):166–172.23143203 | E2
Sands JM, Mandrekar SJ, Kozono D, Integration of immunotherapy into adjuvant therapy for resected non-small-cell lung cancer: ALCHEMIST chemo-IO (ACCIO). Immunotherapy. 2021;13(9):727–734.33878954 | E7
Sankar K, Bryant AK, Strohbehn GW, Real World Outcomes versus Clinical Trial Results of Durvalumab Maintenance in Veterans with Stage III Non-Small Cell Lung Cancer. Cancers. 2022;14(3):26. | E1
Saw SPL, Zhou S, Chen J, Association of Clinicopathologic and Molecular Tumor Features With Recurrence in Resected Early-Stage Epidermal Growth Factor Receptor–Positive Non–Small Cell Lung Cancer. JAMA Network Open. 2021;4(11):e2131892-e2131892.34739062 | E4
Schaake EE, Kappers I, Codrington HE, Tumor response and toxicity of neoadjuvant erlotinib in patients with early-stage non-small-cell lung cancer. Journal of Clinical Oncology. 2012;30(22):2731–2738. | E6
Schoenfeld AJ, Arbour KC, Rizvi H, Severe immune-related adverse events are common with sequential PD-(L)1 blockade and osimertinib. Annals of Oncology. 2019;30(5):839–844.30847464 | E1
Sepesi B, Zhou N, William WN, Jr., Surgical outcomes after nivolumab or nivolumab with ipilimumab treatment in patients with non-small cell lung cancer. Journal of Thoracic & Cardiovascular Surgery. 2022;23:23. | E6
Shen D, Wang J, Wu J, Neoadjuvant pembrolizumab with chemotherapy for the treatment of stage IIB-IIIB resectable lung squamous cell carcinoma. Journal of Thoracic Disease. 2021;13(3):1760–1768.33841966 | E6
Shen H, Zhong X, Ge XQ, Huang JJ, Yuan Y. Surgical resection of lung adenocarcinoma without EGFR mutation after neoadjuvant gefitinib treatment. The clinical respiratory journal. 2010;4(3):192–193.20565499 | E6
Shi T, Zhu S, Guo H, The Impact of Programmed Death-Ligand 1 Expression on the Prognosis of Early Stage Resected Non-Small Cell Lung Cancer: A Meta-Analysis of Literatures. Frontiers in Oncology. 2021;11:567978.33708622 | E2
Shu CA, Gainor JF, Awad MM, Neoadjuvant atezolizumab and chemotherapy in patients with resectable non-small-cell lung cancer: an open-label, multicentre, single-arm, phase 2 trial. Lancet Oncology. 2020;21(6):786–795.32386568 | E6
Sierra-Rodero B, Cruz-Bermudez A, Nadal E, Clinical and molecular parameters associated to pneumonitis development in non-small-cell lung cancer patients receiving chemoimmunotherapy from NADIM trial. Journal for Immunotherapy of Cancer. 2021;9(8):08. | E6
Simoneaux R. Neoadjuvant Nivolumab in Patients With Resectable Non-Small Cell Lung Cancer. Oncology Times. 2018;40(11):41–42. | E7
Stewart P. Neoadjuvant Nivolumab plus Chemotherapy Signifcantly Improves Pathologic Complete Response in Patients with Resectable NSCLC. Oncology Pharmacist. 2021;14(5):9–9. | E7
Su PL, Chen JY, Chu CY, The impact of driver mutation on the treatment outcome of early-stage lung cancer patients receiving neoadjuvant immunotherapy and chemotherapy. Scientific Reports. 2022;12(1):3319.35228655 | E6
Tanvetyanon T. Neoadjuvant Nivolumab plus Chemotherapy in Lung Cancer. New England Journal of Medicine. 2022;387(6):571. | E7
Terrenato I, Ercolani C, Di Benedetto A, A Real-World Systematic Analysis of Driver Mutations' Prevalence in Early- and Advanced-Stage NSCLC: Implications for Targeted Therapies in the Adjuvant Setting. Cancers. 2022;14(12):2971-N.PAG.35740637 | E2
Tfayli A, Al Assaad M, Fakhri G, Neoadjuvant chemotherapy and Avelumab in early stage resectable nonsmall cell lung cancer. Cancer Medicine. 2020;9(22):8406–8411.32991781 | E6
Tong BC, Gu L, Wang X, Perioperative outcomes of pulmonary resection after neoadjuvant pembrolizumab in patients with non-small cell lung cancer. Journal of Thoracic & Cardiovascular Surgery. 2022;163(2):427–436.33985811 | E6
Tsuboi M, Goldman JW, Wu YL, LIBRETTO-432, a phase III study of adjuvant selpercatinib or placebo in stage IB-IIIA RET fusion-positive non-smallcell lung cancer. Future Oncology. 2022;11:11. | E7
van Vugt MJH, Stone JA, De Greef R, Immunogenicity of pembrolizumab in patients with advanced tumors. Journal for Immunotherapy of Cancer. 2019;7(1):212.31395089 | E1
Wang J, Li J, Cai L, Chen S, Jiang Y. The safety and efficacy of neoadjuvant programmed death 1 inhibitor therapy with surgical resection in stage IIIA non-small cell lung cancer. Annals of Translational Medicine. 2021;9(6). | E6
Wen M, Wang L, Wang X, Optimal Adjuvant Therapy in Resected Stage IIIA-N2 Non-Small-Cell Lung Cancer Harboring EGFR Mutations. Oncology Research and Treatment. 2020;43(12):686–693.33197924 | E6
Willers H, Piper-Vallillo A, Rotow J, Integration of EGFR Inhibition With Radiation-Based Multimodality Treatment in Stage III EGFR Mutant NSCLC. International Journal of Radiation Oncology, Biology, Physics. 2021;111(3):e457-e457. | E2
Wislez M, Mazieres J, Lavole A, 1214O Neoadjuvant durvalumab in resectable non-small cell lung cancer (NSCLC): Preliminary results from a multicenter study (IFCT-1601 IONESCO). Annals of Oncology. 2020;31:S794. | E6
Wu J, Hou L, E H, Real-world clinical outcomes of neoadjuvant immunotherapy combined with chemotherapy in resectable non-small cell lung cancer. Lung Cancer. 2022;165:115–123.35123154 | E6
Xie H, Wang H, Xu L, Gefitinib Versus Adjuvant Chemotherapy in Patients With Stage II-IIIA Non-Small-Cell Lung Cancer Harboring Positive EGFR Mutations: A Single-Center Retrospective Study. Clinical Lung Cancer. 2018;19(6):484–492.30369426 | E6
Xiong L, Li R, Sun J, Erlotinib as Neoadjuvant Therapy in Stage IIIA (N2) EGFR Mutation-Positive Non-Small Cell Lung Cancer: A Prospective, Single-Arm, Phase II Study. Oncologist. 2019;24(2):157-e164.30158288 | E6
Xu S-T, Xi J-J, Zhong W-Z, The Unique Spatial-Temporal Treatment Failure Patterns of Adjuvant Gefitinib Therapy: A Post Hoc Analysis of the ADJUVANT Trial (CTONG 1104). Journal of Thoracic Oncology. 2019;14(3):503–512.30521970 | E4
Yamamoto T, Tsukita Y, Katagiri Y, Durvalumab after chemoradiotherapy for locally advanced non-small cell lung cancer prolonged distant metastasis-free survival, progression-free survival and overall survival in clinical practice. BMC Cancer. 2022;22(1):364.35379201 | E1
Yamauchi M, Yamaguchi R, Nakata A, Epidermal growth factor receptor tyrosine kinase defines critical prognostic genes of stage I lung adenocarcinoma. PLoS ONE [Electronic Resource]. 2012;7(9):e43923.23028479 | E7
Yang CJ, McSherry F, Mayne NR, Surgical Outcomes After Neoadjuvant Chemotherapy and Ipilimumab for Non-Small Cell Lung Cancer. Ann Thorac Surg. 2018;105(3):924–929.29258674 | E6
Yang W, Gao Y, Li X, Postoperative survival of EGFR-TKI-targeted therapy in non-small cell lung cancer patients with EGFR 19 or 21 mutations: a retrospective study. World Journal of Surgical Oncology. 2017;15(1):197.29110716 | E6
Yao S, Zhi X, Wang R, Qian K, Hu M, Zhang Y. Retrospective study of adjuvant icotinib in postoperative lung cancer patients harboring epidermal growth factor receptor mutations. Thoracic Cancer. 2016;7(5):543–548.27766784 | E6
Ye JR, Chen PH, Chuang JH, Treatment Effectiveness and Tolerability of Long-term Adjuvant First- and Second-Generation Epidermal Growth Factor Receptor Tyrosine Kinase Inhibitor at Different Doses in Patients With Stage IIA-IIIB Epidermal Growth Factor Receptor-Mutated Lung Adenocarcinoma: A Retrospective Study. Frontiers in Surgery. 2022;9:816018.35360423 | E6
Zeng Z, Yan B, Chen Y, Survival benefit and toxicity profile of adjuvant icotinib for patients with EGFR mutation-positive non-small cell lung carcinoma: a retrospective study. Translational Lung Cancer Research. 2020;9(6):2401–2410.33489802 | E6
Zhai H, Li W, Jiang K, Zhi Y, Yang Z. Neoadjuvant Nivolumab and Chemotherapy in Patients with Locally Advanced Non-Small Cell Lung Cancer: A Retrospective Study. Cancer management and research. 2022;14:515–524.35173485 | E6
Zhang C, Yan LX, Jiang BY, Wu YL, Zhong WZ. Feasibility and Safety of Neoadjuvant Alectinib in a Patient With ALK-Positive Locally Advanced NSCLC. Journal of Thoracic Oncology: Official Publication of the International Association for the Study of Lung Cancer. 2020;15(6):e95-e99.32471573 | E6
Zhang F, Guo W, Zhou B, Three-Year Follow-Up of Neoadjuvant Programmed Cell Death Protein-1 Inhibitor (Sintilimab) in NSCLC. Journal of Thoracic Oncology: Official Publication of the International Association for the Study of Lung Cancer. 2022;17(7):909–920.35550174 | E6
Zhang Y, Fu F, Hu H, Gefitinib as neoadjuvant therapy for resectable stage II-IIIA non-small cell lung cancer: A phase II study. Journal of Thoracic & Cardiovascular Surgery. 2021;161(2):434–442.e432.32340810 | E6
Zhao D, Xu L, Wu J, Comparison of perioperative outcomes among non-small cell lung cancer patients with neoadjuvant immune checkpoint inhibitor plus chemotherapy, EGFR-TKI, and chemotherapy alone: a real-world evidence study. Translational Lung Cancer Research. 2022;11(7):1468–1478.35958337 | E6
Zhao S, Ma G, Guo J, Outcomes of adjuvant epithelial growth factor receptor tyrosine kinase inhibitors (EGFR-TKIs) treatment for EGFR-mutant non-small-cell lung cancer: a propensity-score analysis. Scientific Reports. 2017;7(1):11528.28912511 | E6
Zhao Z, Chen S, Qi H, Phase II trial of toripalimab plus chemotherapy as neoadjuvant treatment in resectable stage III non-small cell lung cancer (NeoTPD01 Study). In: Wolters Kluwer Health; 2021. | E6
Zhou X, Du J, Xu G, Chen C, Zheng B, Chen J. Cost-effectiveness of osimertinib versus placebo in resected EGFR-mutated non-small cell lung cancer in China. Cancer Medicine. 2022;11:11. | E4
Zinner R, Axelrod R, Solomides CC, Neoadjuvant nivolumab (N) plus cisplatin (C)/pemetrexed (P) or cisplatin /gemcitabine (G) in resectable NSCLC. Journal of Clinical Oncology. 2020;38(15_suppl):9051–9051. | E6