# APPENDIX A SEARCH STRATEGY

## SYSTEMATIC REVIEWS

Search for current systematic reviews (limited to last 7 years); Date Searched: 08-22-22
A. Bibliographic Databases: | # | Search Statement | Results
MEDLINE: Systematic Reviews | 1 | Carcinoma, Non-Small-Cell Lung/ or Lung Neoplasms/ | 250378
MEDLINE: Systematic Reviews
MEDLINE: Systematic Reviews | 2 | (lung cancer or lung neoplasm* or lung carcinoma* or nsclc or lung tumor* or lung tumour*).ti,ab,kw. | 218639
Ovid MEDLINE(R) ALL 1946 to August 19, 2022 | 3 | (non small cell* or nonsmall cell*).ti,ab,kw. | 82273
Ovid MEDLINE(R) ALL 1946 to August 19, 2022
Ovid MEDLINE(R) ALL 1946 to August 19, 2022 | 4 | 2 and 3 | 79798
| 5 | 1 or 4 | 270498
| 6 | Neoadjuvant Therapy/ or Chemotherapy, Adjuvant/ | 63639
| 7 | (neoadjuvant or adjuvant).ti,ab,kw. | 189953
| 8 | 6 or 7 | 211194
| 9 | Gefitinib/ or Afatinib/ or Nivolumab/ or Immune Checkpoint Inhibitors/ or Protein Kinase Inhibitors/ | 69196
| 10 | (gefitinib or erolotinib or afatinib or osimertinib or atezolizumab or durvalumab or nivolumab or pembrolizumab or cemiplimab or EGFR tyrosine kinase inhibitors or anti-PD-1 or anti-PD-L1 or checkpoint inhibitor* or check-point inhibitor*).ti,ab,kw. | 45217
| 11 | 9 or 10 | 98653
| 12 | 5 and 8 and 11 | 781
| 13 | [underlined: (systematic review.ti. or meta-analysis.pt. or meta-analysis.ti. or systematic literature review.ti. or this systematic review.tw. or pooling project.tw. or (systematic review.ti,ab. and review.pt.) or meta synthesis.ti. or meta-analy*.ti. or integrative review.tw. or integrative research review.tw. or rapid review.tw. or umbrella review.tw. or consensus development conference.pt. or practice guideline.pt. or drug class reviews.ti. or cochrane database syst rev.jn. or acp journal club.jn. or health technol assess.jn. or evid rep technol assess summ.jn. or jbi database system rev implement rep.jn. or (clinical guideline and management).tw. or ((evidence based.ti. or evidence-based medicine/ or best practice*.ti. or evidence synthesis.ti,ab.) and (((review.pt. or diseases category/ or behavior.mp.) and behavior mechanisms/) or therapeutics/ or evaluation studies.pt. or validation studies.pt. or guideline.pt. or pmcbook.mp.)) or (((systematic or systematically).tw. or critical.ti,ab. or study selection.tw. or ((predetermined or inclusion) and criteri*).tw. or exclusion criteri*.tw. or main outcome measures.tw. or standard of care.tw. or standards of care.tw.) and ((survey or surveys).ti,ab. or overview*.tw. or review.ti,ab. or reviews.ti,ab. or search*.tw. or handsearch.tw. or analysis.ti. or critique.ti,ab. or appraisal.tw. or (reduction.tw. and (risk/ or risk.tw.) and (death or recurrence).mp.)) and ((literature or articles or publications or publication or bibliography or bibliographies or published).ti,ab. or pooled data.tw. or unpublished.tw. or citation.tw. or citations.tw. or database.ti,ab. or internet.ti,ab. or textbooks.ti,ab. or references.tw. or scales.tw. or papers.tw. or datasets.tw. or trials.ti,ab. or meta-analy*.tw. or (clinical and studies).ti,ab. or treatment outcome/ or treatment outcome.tw. or pmcbook.mp.))) not (letter or newspaper article).pt.] | 535251
| 14 | [underlined: 12 and 13] | 51
| 15 | [underlined: limit 14 to english language] | 50
CDSR: Protocols and Reviews | 1 | (Non-Small-Cell Lung Carcinoma or Lung Neoplasms).kw. | 45
EBM Reviews - Cochrane Database of Systematic Reviews 2005 to August 17, 2022 | 2 | (lung cancer or lung neoplasm* or lung carcinoma* or nsclc or lung tumor* or lung tumour*).ti,ab,kw. | 97
EBM Reviews - Cochrane Database of Systematic Reviews 2005 to August 17, 2022
EBM Reviews - Cochrane Database of Systematic Reviews 2005 to August 17, 2022 | 3 | (non small cell* or nonsmall cell*).ti,ab,kw. | 53
EBM Reviews - Cochrane Database of Systematic Reviews 2005 to August 17, 2022
EBM Reviews - Cochrane Database of Systematic Reviews 2005 to August 17, 2022 | 4 | 2 and 3 | 53
EBM Reviews - Cochrane Database of Systematic Reviews 2005 to August 17, 2022
EBM Reviews - Cochrane Database of Systematic Reviews 2005 to August 17, 2022 | 5 | 1 or 4 | 72
| 6 | (Neoadjuvant Therapy or Chemotherapy, Adjuvant).kw. | 91
| 7 | (neoadjuvant or adjuvant).ti,ab,kw. | 296
| 8 | 6 or 7 | 296
| 9 | (Gefitinib or Afatinib or Nivolumab or Immune Checkpoint Inhibitors or Protein Kinase Inhibitors).kw. | 13
| 10 | (gefitinib or erolotinib or afatinib or osimertinib or atezolizumab or durvalumab or nivolumab or pembrolizumab or cemiplimab or EGFR tyrosine kinase inhibitors or anti-PD-1 or anti-PD-L1 or checkpoint inhibitor* or check-point inhibitor*).ti,ab,kw. | 22
| 11 | 9 or 10 | 29
| 12 | 5 and 8 and 11 | 1

Search for current systematic reviews (limited to last 7 years); Date Searched: 08-22-22
B. Non-bibliographic databases | Evidence | Results
AHRQ: evidence reports, technology assessments, U.S Preventative Services Task Force Evidence Synthesis | http://www.ahrg.gov/research/findings/evidence-based-reports/search.html; Search: non-small-cell lung cancer AND (neoadjuvant OR adjuvant) | 0
CADTH | https://www.cadth.ca; Search: non-small-cell lung cancer AND (neoadjuvant OR adjuvant); Nivolumab-Ipilimumab for Non-Small Cell Lung Cancer – Details. 2021. https://www.cadth.ca/nivolumab-ipilimumab-non-small-cell-lung-cancer-details; Keytruda for Non-Squamous NSCLC – Details. 2019. https://www.cadth.ca/keytruda-non-squamous-nsclc-details; Keytruda for Squamous NSCLC – Details. 2020. https://www.cadth.ca/keytruda-squamous-nsclc-details | 3
EPPI-Centre | http://eppi.ioe.ac.uk/cms/Default.aspx?tabid=62; Search: lung cancer | 0
NLM | http://www.ncbi.nlm.nih.gov/books; Search: non-small-cell lung cancer AND (adjuvant OR neoadjuvant) | 0
VA Products - VATAP, PBM and HSR&D publications | A. http://www.hsrd.research.va.gov/research/default.cfm; B. http://www.research.va.gov/research_topics/; Search: luna cancer | 0

Search for systematic reviews currently under development (includes forthcoming reviews & protocols); Date Searched: 08-22-22
D. Under development: | Evidence: | Results:
AHRQ topics in development; (EPC Status Report) | KV emailed 08-22-22; CA responded 08-22-22, no duplication | 0
PROSPERO (SR registry) | http://www.crd.york.ac.uk/PROSPERO/; Search: non-small-cell lung cancer AND (neoadjuvant OR adjuvant); Chunhua Xu, wei liu, Qian Zhang, Tiantian Zhang, Li Li, Chunhua Xu. A systematic review and meta-analysis of neoadjuvant chemoimmunotherapy in stage III non-small cell lung cancer.. PROSPERO 2022 CRD42022325531 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42022325531; Xuhao Wang, Fanqi Meng. A systematic review and network meta-analysis protocol of neoadjuvant chemoimmunotherapy for patients with resectable non-small-cell lung cancer. PROSPERO 2022 CRD42022328166 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42022328166; Xuhao Wang, Fanqi Meng. A systematic review and network meta-analysis protocol of neoadjuvant Immune Checkpoint Inhibitor therapy for patients with resectable non-small-cell lung cancer. PROSPERO 2021 CRD42021258132 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42021258132; Guishi Wang, Tiantian Wang. A systematic review and network meta-analysis protocol of various neoadjuvant therapies Immune for patients with resectable non-small-cell lung cancer. PROSPERO 2021 CRD42021269087 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42021269087; Rui-Lian Chen, Ling-Ling Sun, Yang Cao, Jie-Tao Lin, Ying Zhang, Jing-Xu Zhou, Si-Yu Wang, Wei Hou, Li-Zhu Lin. Adjuvant EGFR-TKI for EGFR-mutant patients with resected non-small cell lung cancer: a meta-analysis from randomized controlled trials. PROSPERO 2020 CRD42020181942 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42020181942; Rui-Lian Chen, Han-Rui Chen, Ling-Ling Sun, Yang Cao, Jie-Tao Lin, Ying Zhang, Jing-Xu Zhou, Si-Yu Wang, Wei Hou, Li-Zhu Lin. Adjuvant EGFR-TKI for EGFR-mutant patients with resected non-small cell lung cancer: a meta-analysis from randomized controlled trials. PROSPERO 2020 CRD42020190776 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42020190776; Ran Zhong, Wenhua Liang, Caichen Li, Jianxing He. Adjuvant EGFR-TKIs versus standard chemotherapy for patients with resected NSCLC: a meta-analysis. PROSPERO 2021 CRD42021240657 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42021240657; Ye Zhao, Hai-ming Feng, Jin-hui Tian, Qin Yu, Long Ge, Bin Li, Cheng Wang, Ke-hu Yang, Jian-kai Wang. Adjuvant treatments after chemoradiotherapy in patients with locally advanced inoperable non-small cell lung cancer (NSCLC): a svstematic review and network meta-analysis.. PROSPERO 2021 CRD42021239433 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42021239433; Jessa Gilda Pandy,, Joanmarie Balolong, Marcelo Imasa. Adjuvant Tyrosinen Kinase Inhibitors in Nonsquamous non-small cell lung cancer with EGFR driver mutations: A Meta-analysis of randomized trials. PROSPERO 2020 CRD42020197421 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42020197421; Yongxing Bao, Shuang Sun, Xu Yang, Yunsong Liu, Yang Wang, Zhouguang Hui. Comparation of Different adjuvant EGFR-TKIs for Resected Non small cell lung cancer – a Systematic Review and Network Meta-Analysis. PROSPERO 2022 CRD42022300589 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42022300589; Yi Yang, Yingyao Chen, Dai Lian, Ying Tao. Comparative safety and efficacy of PD-1/PD-L1 inhibitors in the first-line treatment for locally advanced or metastatic non-squamous non-small cell lung cancer: A systematic review and network meta-analysis. PROSPERO 2021 CRD42021275631 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42021275631; Manting Wang, Liang Hengrui, Liang Wenhua, He Jianxing. Comparison of immune-related adverse events (irAEs) of combination of PD-(L)1 inhibitors and chemotherapy versus PD-(L)1 inhibitors for non-small cell lung cancer: a meta-analysis of randomised controlled trials. PROSPERO 2020 CRD42020139923 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42020139923; Michela Febbraro, Arani Sathiyapalan, Rosalyn Juergens. Effects of anaplastic lymphoma kinase (ALK) tyrosine kinase inhibitors (TKIs) in the first-line treatment of metastatic ALK positive non-small cell lung cancer (NSCLC): A systematic review and meta-analysis. PROSPERO 2021 CRD42021247914 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42021247914; Pengfei ZHAO, Hongchao ZHEN, Hong ZHAO, Lei ZHAO, Bangwei CAO. Efficacy and safety of adjuvant EGFR-TKIs for resected non-small cell lung cancer: A systematic review and meta-analysis based on randomized control trials. PROSPERO 2022 CRD42022309877 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42022309877; Dongyu Li, Nan Sun, Jie He. Efficacy and safety of adjuvant therapy for epidermal growth factor receptor mutated, non-small cell lung cancer: systematic review and network meta-analysis.. PROSPERO 2022 CRD42022334185 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42022334185; Chris Dickhoff, Idris Bahce, Suresh Senan, Ezgi Ulas. Efficacy and safety of neoadjuvant immune checkpoint inhibitors in operable non-small cell lung cancer: a systematic review. PROSPERO 2021 CRD42021235759 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42021235759; Peng Xie, Xiaolin Li, Wenjie Tang, Jinming Yu, Xindong Sun, Xueqi Xie, Haiyan Zeng, Jie Liu, Yinjun Dong, Guanglei Zhao, Chungang Wang, Dongdong Du. EGFR inhibitors as adjuvant therapy for resected non-small cell lung cancer harboring EGFR mutations: a meta-analysis. PROSPERO 2018 CRD42018093144 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42018093144; Boxue He, Qidong Cai, Pengfei Zhang. EGFR-TKIs as neoadjuvant therapy for non-small cell lung cancer: a meta-analysis. PROSPERO 2020 CRD42020197989 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42020197989; Jun Dang, He Wang, Jun Chen, Tingting Liu, Guang Li. Neoadjuvant immunotherapy and neoadjuvant chemotherapy in resectable non-small cell lung cancer: A systematic review and hypothesis-generating meta-analysis. PROSPERO 2021 CRD42021278661 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42021278661; Dong Chen, Jianfei Shen. Neoadjuvant treatments of EGFR-Mutated IIIa NSCLC : A meta-analysis. PROSPERO 2021 CRD42021221136 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42021221136; Xiaohui Jia, Hong Xu. Safety and efficacy of neoadjuvant immune checkpoint inhibitors in resectable non-small cell lung cancer : a Meta analysis. PROSPERO 2020 CRD42020173557 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42020173557; Xiaoshun Shi, Xiaoying Dong, Jianxue Zhai, Zhen Ni. The efficacy and safety of neoadjuvant EGFR-TKIs for patients with non-small cell lung cancer (NSCLC) : a meta analysis. PROSPERO 2020 CRD42020187031 Available from: https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42020187031 | 22

## PRIMARY STUDIES

Search for primary literature; Date searched: 08-22-22
MEDLINE
# | Search Statement | Results
1 | Carcinoma, Non-Small-Cell Lung/ or Lung Neoplasms/ | 250378
2 | (lung cancer or lung neoplasm* or lung carcinoma* or nsclc or lung tumor* or lung tumour*).ti,ab,kw. | 218639
3 | (non small cell* or nonsmall cell*).ti,ab,kw. | 82273
4 | 2 and 3 | 79798
5 | 1 or 4 | 270498
6 | Neoadjuvant Therapy/ or Chemotherapy, Adjuvant/ | 63639
7 | (neoadjuvant or adjuvant).ti,ab,kw. | 189953
8 | 6 or 7 | 211194
9 | Gefitinib/ or Afatinib/ or Nivolumab/ or Immune Checkpoint Inhibitors/ or Protein Kinase Inhibitors/ | 69196
10 | (gefitinib or erolotinib or afatinib or osimertinib or atezolizumab or durvalumab or nivolumab or pembrolizumab or cemiplimab or EGFR tyrosine kinase inhibitors or anti-PD-1 or anti-PD-L1 or checkpoint inhibitor* or check-point inhibitor*).ti,ab,kw. | 45217
11 | 9 or 10 | 98653
12 | 5 and 8 and 11 | 781
| limit 12 to English language | 725
CINAHL
# | Search Statement | Results
1 | (MH “Carcinoma, Non-Small-Cell Lung”) OR (MH “Lung Neoplasms”) | 49649
2 | lung cancer or lung neoplasm* or lung carcinoma* or nsclc or lung tumor* or lung tumour* | 68650
3 | non small cell* or nonsmall cell* | 26497
4 | S2 and S3 | 25890
5 | S1 or S4 | 55949
6 | (MH “Neoadjuvant Therapy”) OR (MH “Chemotherapy, Adjuvant”) | 17798
7 | neoadjuvant or adjuvant | 46413
8 | S6 or S7 | 46413
9 | (MH “Gefitinib”) OR (MH “Afatinib”) OR (MH “Nivolumab”) OR (MH “Immune Checkpoint Inhibitors”) OR (MH “Protein Kinase Inhibitors”) | 8518
10 | gefitinib or erolotinib or afatinib or osimertinib or atezolizumab or durvalumab or nivolumab or pembrolizumab or cemiplimab or EGFR tyrosine kinase inhibitors or anti-PD-1 or anti-PD-L1 or checkpoint inhibitor* or check-point inhibitor* | 14085
11 | S9 or S10 | 19046
12 | S5 and S8 and S11 | 265
13 | limit S12 to English language | 249