# ABBREVIATIONS TABLE

AJCC/UICC: American Joint Committee on Cancer/Union for International Cancer Control
EGFR: Epidermal growth factor receptor
EGFRm+: Epidermal growth factor receptor mutation-positive
ESP: Evidence Synthesis Program
ICI: Immune checkpoint inhibitor
NSCLC: Non-small cell lung cancer
PD-L1: Programmed death ligand 1
TKI: Tyrosine kinase inhibitor