# REFERENCES

1 Forster AJ, Murff HJ, Peterson JF, The incidence and severity of adverse events affecting patients after discharge from the hospital. Ann Intern Med. 2003;138(3):161–7.12558354
2 Woods CE, Jones R, O'Shea E, Nurse-led postdischarge telephone follow-up calls: A mixed study systematic review. J Clin Nurs. 2019;28(19–20):3386–3399.31162748
3 Fingar KR, Barrett ML, Jiang HJ. A Comparison of All-Cause 7-Day and 30-Day Readmissions, 2014. October 2017. In: Healthcare Cost and Utilization Project (HCUP) Statistical Briefs [Internet]. Rockville (MD): Agency for Healthcare Research and Quality (US); Statistical Brief #230. Available at: https://www.ncbi.nlm.nih.gov/books/NBK487973/pdf/Bookshelf_NBK487973.pdf. Accessed December 7, 2023.
4 Donzé J, Aujesky D, Williams D, Potentially Avoidable 30-Day Hospital Readmissions in Medical Patients: Derivation and Validation of a Prediction Model. JAMA Intern Med. 2013;173(8):632–638.23529115
5 Beauvais B, Whitaker Z, Kim F, Is the Hospital Value-Based Purchasing Program Associated with Reduced Hospital Readmissions? J Multidiscip Healthc. 2022;15:1089–1099.35592815
6 Rising KL, White LF, Fernandez WG, Emergency department visits after hospital discharge: a missing part of the equation. Ann Emerg Med. 2013;62(2):145–50.23562776
7 Gonçalves-Bradley DC, Lannin NA, Clemson L, Discharge planning from hospital. Cochrane Database Syst Rev. 2022;2(2):Cd000313.35199849
8 Kim CS, Flanders SA. In the Clinic. Transitions of care. Ann Intern Med. 2013;158.
9 Centers for Medicare & Medicaid Services. Hospital Readmissions Reduction Program (HRRP). [Website] Available at: https://www.cms.gov/medicare/payment/prospective-payment-systems/acute-inpatient-pps/hospital-readmissions-reduction-program-hrrp. Accessed December 7, 2023.
10 U.S. Department of Health and Human Services. Medicare Program; Revisions to Payment Policies Under the Physician Fee Schedule, DME Face-to-Face Encounters, Elimination of the Requirement for Termination of Non-Random Prepayment Complex Medical Review and Other Revisions to Part B for CY 2013. Federal Register / Vol. 77, No. 222 / Friday, November 16, 2012 / Rules and Regulations. Available at: https://www.govinfo.gov/content/pkg/FR-2012-11-16/pdf/2012-26900.pdf. Accessed December 7, 2023.
11 Jack BW, Paasche-Orlow MK, Mitchell SM, An overview of the Re-Engineered Discharge (RED) Toolkit. (Prepared by Boston University under Contract No. HHSA290200600012i.) Rockville, MD: Agency for Healthcare Research and Quality; March 2013. AHRQ Publication No. 12(13)-0084. Available at: https://www.ahrq.gov/sites/default/files/publications/files/redtoolkit.pdf. Accessed February 28, 2024.
12 Jack BW, Chetty VK, Anthony D, A reengineered hospital discharge program to decrease rehospitalization: a randomized trial. Ann Intern Med. 2009;150(3):178–87.19189907
13 Department of Veterans Affairs. Veterans Health Administration. Available at: https://www.va.gov/health/aboutvha.asp#:~:text=The%20Veterans%20Health%20Administration%20(VHA,Veterans%20enrolled%20in%20the%20VA. Accessed February 28, 2024.
14 Guise JM, Butler ME, Chang C, AHRQ series on complex intervention systematic reviews-paper 6: PRISMA-CI extension statement and checklist. J Clin Epidemiol. 2017;90:43–50.28720516
15 Higgins JPT, López-López JA, Becker BJ, Synthesising quantitative evidence in systematic reviews of complex health interventions. BMJ Glob Health. 2019;4(Suppl 1):e000858.
16 Hawe P, Shiell A, Riley T. Complex interventions: how "out of control" can a randomised controlled trial be? BMJ. 2004;328(7455):1561–3.15217878
17 ROBINS-I: Risk Of Bias In Non-Randomized Studies of Interventions. Available at: https://methods.cochrane.org/bias/risk-bias-non-randomized-studies-interventions. Accessed December 19, 2023.
18 RoB 2: A revised Cochrane risk-of-bias tool for randomized trials Available at: https://methods.cochrane.org/bias/resources/rob-2-revised-cochrane-risk-bias-tool-randomized-trials. Accessed December 19, 2023.
19 metafor. Meta-analysis package for R. Version 4.2–0. The Comprehensive R Archive Network; 2023. Available at: https://wviechtb.github.io/metafor/index.html. Accessed December 27, 2023.
20 Balshem H, Helfand M, Schünemann HJ, GRADE guidelines: 3. Rating the quality of evidence. J Clin Epidemiol. 2011;64(4):401–6.21208779
21 Bell S, Schnipper J, Goggins K, Effect of Pharmacist Counseling Intervention on Health Care Utilization Following Hospital Discharge: A Randomized Control Trial. J Gen Intern Med. 2016;31(5):470–477.26883526
22 Clari M, Frigerio S, Ricceri F, Follow-up telephone calls to patients discharged after undergoing orthopaedic surgery: double-blind, randomised controlled trial of efficacy. J Clin Nurs. 2015;24(19–20):2736–44.25705815
23 Danielsen SO, Moons P, Sandvik L, Impact of telephone follow-up and 24/7 hotline on 30-day readmission rates following aortic valve replacement -A randomized controlled trial. Int J Cardiol. 2020;300:66–72.31387822
24 Farris KB, Carter BL, Xu Y, Effect of a care transition intervention by pharmacists: an RCT. BMC Health Serv Res. 2014;14:406.25234932
25 Haag JD, Davis AZ, Hoel RW, Impact of Pharmacist-Provided Medication Therapy Management on Healthcare Quality and Utilization in Recently Discharged Elderly Patients... [including commentary by James T. Kenney, Jr]. Am Health Drug Benefits. 2016;9(5):259–268.27625743
26 Lee KK, Thomas RC, Tan TC, The Heart Failure Readmission Intervention by Variable Early Follow-up (THRIVE) Study: A Pragmatic Randomized Trial. Circ Cardiovasc Qual Outcomes. 2020;13(10):e006553.32967439
27 Lindpaintner LS, Gasser JT, Schramm MS, Discharge intervention pilot improves satisfaction for patients and professionals. Eur J Intern Med. 2013;24(8):756–62.24075842
28 Lundby C, Filipsen J, Rasmussen S, Medication-Focused Patient Counseling Upon Discharge: A Feasibility Study of Effect on Patient Satisfaction. Pharmacy. 2020;8(1):14.32019094
29 Robinson TE, Zhou L, Kerse N, Evaluation of a New Zealand program to improve transition of care for older high risk adults. Australas J Ageing. 2015;34(4):269–74.26525602
30 Sarangarm P, London MS, Snowden SS, Impact of pharmacist discharge medication therapy counseling and disease state education: Pharmacist Assisting at Routine Medical Discharge (project PhARMD). Am J Med Qual. 2013;28(4):292–300.23033542
31 Soong C, Kurabi B, Wells D, Do post discharge phone calls improve care transitions? A cluster-randomized trial. PLoS ONE [Electronic Resource]. 2014;9(11):e112230.25386678
32 Sorknaes AD, Bech M, Madsen H, The effect of real-time teleconsultations between hospital-based nurses and patients with severe COPD discharged after an exacerbation. J Telemed Telecare. 2013;19(8):466–74.24227799
33 Yiadom M, Domenico HJ, Byrne DW, Impact of a Follow-up Telephone Call Program on 30-Day Readmissions (FUTR-30): A Pragmatic Randomized Controlled Real-world Effectiveness Trial. Med Care. 2020;58(9):785–792.32732787
34 Weiss ME, Bobay KL, Bahr SJ, A Model for Hospital Discharge Preparation: From Case Management to Care Transition. J Nurs Adm. 2015;45(12):606–14.26502068
35 Fox MT, Persaud M, Maimets I, Effectiveness of early discharge planning in acutely ill or injured hospitalized older adults: a systematic review and meta-analysis. BMC Geriatr. 2013;13:70.23829698
36 Lockwood C, Mabire C. Hospital discharge planning: evidence, implementation and patient-centered care. JBI Evid Synth. 2020;18(2):272–274.32229736
37 Coleman EA, Parry C, Chalmers S, The care transitions intervention: results of a randomized controlled trial. Arch Intern Med. 2006;166(17):1822–8.17000937
38 Naylor MD, Brooten D, Campbell R, Comprehensive discharge planning and home follow-up of hospitalized elders: a randomized clinical trial. JAMA. 1999;281(7):613–20.10029122
39 Bahr SJ, Solverson S, Schlidt A, Integrated literature review of postdischarge telephone calls. West J Nurs Res. 2014;36(1):84–104.23833254
40 DeLia D, Tong J, Gaboda D, Post-discharge follow-up visits and hospital utilization by Medicare patients, 2007–2010. Medicare Medicaid Res Rev. 2014;4(2).