# ACKNOWLEDGMENTS

The authors are grateful to Liz Wing for editorial support, Matthew Luedke for reference screening efforts, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Laura Coyle, DNP, RN, CNL, CPHQ, CLSSBB
  Quality Manager
  VHACO Office of Primary Care
- Traci Solt, DNP, FACHE, NEA-BC, CRRN, CCM, AMC-BC
  Director, Clinical Services
  VHACO Office of Primary Care

## Technical Expert Panel

To ensure scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Anuj Dalal, MD
  Hospital Medicine
  Brigham and Women’s Hospital
- Brianna Gass, MPH
  Senior Manager, Health Management
  Telligen Corporation
- Sharon Kleinhans, RN
  Nurse Manager
  VA Medical Center Tomah