# DISCUSSION

The transition from hospital to home is a vulnerable period for patients, with many experiencing a variety of health-related problems in the period directly following a hospital discharge. Follow-up contacts to patients in the week after hospital discharge has been widely used as a strategy to mitigate transition-related issues. Our systematic review identified 13 relevant studies that assessed the impact of post-discharge contacts (PDCs) with adult patients after an acute hospitalization. Most included studies were randomized trials (N = 11), with only 1 rated as high risk of bias. More than half of studies (N = 8) focused on populations at elevated medical risk (eg, 65 years of age and older, chronic obstructive pulmonary disease [COPD], heart failure). None of the included studies focused on populations with an acute psychiatric hospitalization. All but 1 study used telephone to deliver the PDC intervention, and most (N = 11) interventions consisted of a single contact conducted in the first 3 days after hospital discharge. Based on a modest but consistent body of evidence, post-discharge follow-up contacts delivered in the first 7 days after leaving the hospital likely have no impact on 30-day hospital readmissions (moderate COE; randomized trials), 30-day ED use (moderate COE; randomized trials), or patient satisfaction with care.

There are several considerations for interpreting our findings on the lack of impact of PDC interventions, which may also guide future research on the topic. First, discharge planning that occurs during inpatient care is a routine procedure in most health systems.^34,35^ These discharge planning procedures vary but generally include medication review and counseling, patient and/or family caregiver education, and coordinating care with community healthcare providers.^35^ In the studies included in our review, about half describe some type of pre-discharge planning protocol. It is likely that similar pre-discharge procedures occurred in some fashion in most studies, as this has grown to be the standard of care and is highlighted in the AHRQ Project RED toolkit.^11,36^ In fact, the vast majority of discharge planning steps in the Project RED toolkit are designated as pre-discharge tasks. Thus, the addition of a single post-discharge contact would be a minor component of a broader discharge planning intervention with little potential to have an isolated impact on hospital readmission or ED use.

Second, while most studies reported having a standard protocol for PDC interventions, virtually none of the included studies rigorously assessed whether patients actually received a post-discharge contact (ie, intervention adherence) or whether the post-discharge contact delivered the call according to the protocol (ie, intervention fidelity). Factors related to intervention implementation like adherence and fidelity can impact intervention effectiveness. One large, low risk of bias randomized study included in this review did report implementation information and also conducted a post hoc analysis of patients who were reached versus not reached for their telephone-delivered post-discharge contact.^33^ Higher rates of hospital readmissions were observed among the patients who were not reached for their post-discharge call.

Next, most of the PDC interventions included in this review were delivered by telephone. Telephone may be an effective modality for some important post-discharge functions (eg, patient education, verification of follow-up appointments), but may be less effective for other critical PDC functions like medication review (eg, unable to see medication labels) or symptom monitoring (eg, visual exam not possible). In the 1 study included in this review that compared telephone to in-person PDC, there was no difference in 30-day hospital readmissions.^26^ Yet, adherence to an office visit in the first 7 days after discharge was significantly lower than adherence to telephone-delivered PDC (79% vs 92% respectively). Additionally, while many patients may be likely to engage over telephone, other patients might respond better to alternative modalities like text messaging, email, or electronic health record smartphone applications. Some patients, such as those experiencing homelessness or severe mental health issues, may not have reliable access to a telephone or have contact information that changes frequently. Last, most studies included in this review focused on patients identified as higher risk based on a variety of factors such as age and medical comorbidities (eg, COPD, heart failure). It is likely that these patients may need more intensive approaches in the transition from hospital to home that cannot be delivered in a single-contact approach. In fact, there is evidence from earlier studies published prior to 2011 that more intensive transition care interventions that include multiple contact before and after hospital discharge are effective in reducing 30-day rehospitalization.^37,38^

Limitations

It is important to note limitations of both the identified literature and our approach to conducting this review. In addition to the study limitations described in the previous section, many studies were small (median sample size of 311) and only 1 study reported subgroups by patient characteristics. Additional research that enrolls sufficient numbers of patients from important subgroups (eg, by age, race, social support status, health literacy, insurance status) could clarify whether there are patients that are likely to benefit from single-contact approaches versus more intensive post-discharge approaches. We identified no studies that assessed PDC for patients with acute psychiatric hospitalizations, a priority of the nominating operational partners. Also, we identified no studies conducted within the VHA health care system. Findings may be less applicable to the VHA population, where historical care, hospital course, and follow-up plans may be available to the PDC interventionist via the Veteran’s comprehensive electronic health record. Last, our definition of PDC did not include interventions that were centered on electronic symptom monitoring only; we required bidirectional communications. Thus, we may have missed some interventions that were focused on remote symptom monitoring.

We constrained our review to studies published after 2011 to align with national policy shifts in the use of PDC in the United States. In date-limiting our search, we likely missed some prior relevant studies. We also limited our eligibility criteria to randomized and EPOC nonrandomized design standards (ie, nonrandomized trials, controlled before-after studies, interrupted time-series, or repeated-measures studies), missing observational studies which may contribute useful information. Yet our findings are consistent with prior reviews that included earlier studies and observational and qualitative designs. These reviews generally found no consistent impact of post-discharge follow-up contacts, though these reviews noted the generally weak methodological quality and high statistical heterogeneity of previous studies.^2,39^ Our systematic review extends these findings by including higher quality study designs (ie, EPOC design standards) and by including an exploration of treatment effectiveness based on key intervention characteristics (eg, content, interventionists, timing of intervention) identified by VHA operational partners. Although there were too few studies in each subgroup to allow for firm conclusions, the consistency of effects across groups suggests that these study characteristics have little influence on the effects of PDC.

## FUTURE RESEARCH

This comprehensive review of the literature identified several gaps in the current evidence that warrant future investigation, which are described below using the population, intervention, comparator, and outcome (PICO) framework (Table 3).

Table 3 Evidence Gaps

Population | - Patients with psychiatric hospitalizations; - Sufficiently powered subgroup analyses by key patient populations related to the following:; ○ Age; ○ Comorbidity (ie, older adult patients with multiple chronic conditions); ○ Hospital length of stay; ○ Race and ethnicity; ○ Family social support; ○ Medical and health literacy; ○ Higher vs lower risk of readmission based on a combination of factors
Intervention | - Multi-contact approaches; - Multimodal approaches (eg, digital vs non-digital approaches; automated vs in-person); - Video- and other modality-delivered (eg, text) interventions; - Integration of family caregiver as needed co-recipient of PDC intervention
Comparator | - Head-to-head comparisons of video vs in-person vs phone modalities; - Variable doses of post-discharge contacts (eg, 1 contact vs daily contacts; received vs did not receive post-discharge contacts); - Direct comparison of optimal timing of post-discharge interventions; - Direct comparison of the additive effects of post-discharge functions (ie, medication review, symptom monitoring, coordination of social and health services); - Adjustment for intensity and type of pre-discharge contacts
Outcomes | - Well-specified measures of patient experience with the PDC intervention only; - Patient comprehension of discharge plan and adherence to that plan; - Intervention fidelity to intended content; - Intervention adherence (ie, PDC completed); - Process outcomes of what problems were detected and addressed during PDC approaches that may inform future utility of these brief interventions

## CONCLUSIONS

Brief post-discharge follow-up calls are widely used in the United States and elsewhere. In the United States, this push toward follow-up contacts after a hospitalization likely is due to national policy changes that promoted post-discharge contacts as part of the Patient Protection and Affordable Care Act (ACA).^40^ In 2013, Medicare approved procedure codes for transitional care management services consisting of communication with the patient or caregiver within 2 business days of hospital discharge. Yet our review demonstrated little supporting evidence that such brief, often 1-call follow-ups impacted key health care outcomes of hospital readmissions and ED use at 30 days, or patient satisfaction with care. Our findings should be contextualized further, as there are many unaddressed questions on the utility of post-discharge approaches and limitations of the existing literature included in this systematic review. While our review did not find evidence of significant impacts of brief PDC approaches, health care systems like the VHA should consider the cost effectiveness of these relatively light-touch approaches on costly outcomes such as rebound hospital admissions and ED use. Such considerations of widespread universal brief post-discharge contacts should be balanced with the potential to target investments in more intensive post-discharge approaches focused on patients most likely to benefit from these interventions.