# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Appendix.

## OVERVIEW OF INCLUDED STUDIES

Our search identified 104 potentially relevant articles after deduplication and title and abstract screening. Of these, 13 primary studies (in 13 publications) met eligibility criteria.^21–33^ Characteristics of included studies are shown in Table 1. None of the identified studies were relevant to KQ2. One study was a cluster-randomized trial, 10 were randomized trials, 1 was a nonrandomized trial, and 1 was an interrupted time-series. Six studies were conducted in the USA, 5 in Europe, 1 in New Zealand, and 1 in Canada. No studies were conducted among VHA populations. Ten studies employed medication review, 9 used coordination of care, and 7 included symptom monitoring. Eleven studies reported hospitalization outcomes, 7 reported ED utilization, 4 reported composite outcomes of unplanned health care use, and 4 reported on patient satisfaction. The median sample size of included studies was 311 (range: 25–3,054). Eight studies focused on patient populations at elevated medical risk.^21,23–27,29,32^ We did not identify any studies that focused on patients discharged from an acute psychiatric hospitalization.

## KEY QUESTION 1: EFFECTS OF POST-DISCHARGE CONTACTS AMONG ADULTS WITH ACUTE MEDICAL HOSPITALIZATIONS

### Key Findings

- We identified 13 studies that assessed the impact of PDC interventions on outcomes of interest. None of the studies focused on populations with an acute psychiatric hospitalization. Most (N = 11) studies were randomized trials, with only 1 rated as high ROB.
  ○ All but 1 PDC intervention used telephone-delivered PDC; most (N = 11) PDC approaches consisted of a single contact conducted in the first 3 days after hospital discharge.
  ○ The most common component of PDC was medication review; only 3 studies included all 3 hypothesized core PDC functional components.
- In a meta-analysis, PDC interventions within the 7 days after hospitalization were not associated with a reduction in 30-day hospital readmissions or ED utilization when compared with usual care. Certainty of evidence supporting this conclusion was considered moderate, based primarily on the consistency of results across randomized studies.
- Only 4 studies assessed the impact of PDC on patient satisfaction, and only 1 small study reported higher patient satisfaction among patients exposed to post-discharge contacts.
- Exploration of subgroup differences by intervention characteristics also demonstrated no differential impact on PDC effectiveness on 30-day hospital readmissions or ED use.

### General Characteristics

Of the 13 unique studies we included, 11^21,23–27,29–33^ evaluated the effect of PDC interventions on 30-day hospital readmissions; 7^21,24,25,29–31,33^ on 30-day ED use; 4^21,24,25,30^ on a composite outcome of ED use, readmissions, or unplanned office visits; and 4^22,27,28,33^ on patient satisfaction with care (Appendix). Eleven studies were randomized trials^21–28,31–33^ (of which 1^31^ was a cluster-randomized trial),^31^ with 1^28^ rated as high ROB and 3 ^21,24,33^ rated as low ROB. We also identified 2 eligible nonrandomized designs: 1^30^ nonrandomized trial and 1^29^ interrupted time-series study; both were rated as serious ROB. Common quality concerns among the RCTs included (1) bias due to deviations from the intended PDC interventions; (2) missing outcome data; and (3) bias from potential selective reporting of results. Among the 2 nonrandomized designs, common sources of bias were (1) influence of potential unaccounted confounders; (2) deviations from intended interventions; (3) missing data; and (4) issues with outcomes measurement. (See Appendix for details on ROB rating for each included study.)

The predominant modality of delivery for these PDC interventions was telephone (N = 10^21,23–27,29–31,33^); 1^32^ study employed videoconferencing. Studies varied in timing of PDC (range: 24 hours to 7 days post-discharge) with most (N = 9) initiating contact in the first 3 days post-discharge. Personnel involved in the PDC interventions included pharmacists,^24–26,28,30^ nurses,^22,26,27,29,32,33^ and non-clinical staff (ie, study coordinators,^21,23^ patient navigators^31^). Four studies used more than 1 type of personnel.^21,23,24,26^

Most PDC interventions (N = 10^21–23,25–28,30,31,33^) consisted of a single telephone contact, with 2^23,27^ studies having additional patient-driven contact with a hotline. One^29^ study had 2 direct telephone contacts on the first and third day post-discharge, and 1^32^ study used daily videoconference contacts for a range of 5 to 9 days. Many studies also had extensive pre-discharge components consisting of enhanced interactions with a pharmacist for medication counseling or discharge planning counseling with hospital providers. Eight interventions reported using a structured protocol with a mix of assessments conducted during the contact.^21,23,25–27,31–33^ Core functional components of the contacts varied; the most common component across interventions was some type of medication review process (N = 10^21,22,24–30,33^). The second most common component was coordination of services (N = 9^24,26–33^). Only 3 interventions stated that the contacts included all 3^24,26,29^ core functional components of the PDC (ie, medication review, coordination of services, symptom monitoring). All interventions used usual care as the comparator, with 1^26^ study operationalizing usual care as an in-person appointment with a patient’s usual primary care provider. Additional details of these interventions are in the Appendix.

For KQ1, we present detailed results ordered by major outcomes. Details on study characteristics are in the Appendix.

Table 1 Evidence Profile

Number of Studies | 13 unique studies (13 articles)
Key Question | KQ1 (N = 13); KQ2 (N = 0)
Study Designs | Cluster-randomized trial (N = 1), randomized trial (N = 10), nonrandomized trial (N = 1), interrupted time-series (N = 1)
Countries | USA (N = 6), Europe (N = 5), New Zealand (N = 1), Canada (N = 1)
Intervention Categories | Medication review (N = 10), coordination of care (N = 9), monitoring (N = 7)
Outcome Categories^a^ | Hospitalization (N = 11), ED use (N = 7), composite health care utilization (N = 4), patient satisfaction (N = 4)
ROBINS I Risk of Bias | Low (N = 0), moderate (N = 0), serious (N = 2), critical (N = 0)
ROB 2 Risk of Bias | Low (N = 3), some concerns (N = 7), high (N = 1)

Notes.

a Eight studies reported more than 1 outcome type.

### KQ1a: Effects of PDC on Hospital Readmission, Emergency Care Use, and Patient Satisfaction

#### Hospital Readmission

Eleven studies measured all-cause hospital readmissions at about 30 days (range: 28–30 days).^21,23–27,29–33^ Individually, none of the 11 PDC interventions led to significant reductions in 30-day readmission rates relative to usual care. Although PDC interventions and personnel involved varied, 8^21,23–26,31–33^ of the 9 randomized trials were deemed to have sufficient conceptual homogeneity and provided enough information to perform meta-analysis. Pooled analysis of 7,336 patients demonstrated no significant impact of PDC on 30-day hospital readmissions (OR = 0.94, 95% CI [0.83,1.07]). As shown in Figure 1, effect estimates were generally consistent across studies (95% prediction interval [PI] [0.83, 1.07]).

Figure 1 Effects of PDC interventions in First 7 Days on 30-Day Hospital Readmission (RCTs Only)

These results are corroborated by the results of the nonrandomized trial and interrupted time-series studies that were not included in the meta-analysis.^29,30^ These studies also found no significant impact of PDC on 30-day readmissions. Similarly, 2 studies that also looked at disease-specific readmissions did not identify a reduction in readmissions for the studied conditions.^26,32^ The small randomized trial (N = 57^27^) excluded from the pooled analysis reported greater 30-day hospitalizations in the PDC group compared to usual care (p = 0.026), though a point estimate and number of readmissions in each group were not provided. Only 1 study performed sub-analyses and found no significant associations for sex or age.^26^ Detailed results of all studies are in the Appendix.

#### Emergency Care Use

Seven studies measured all-cause ED use at approximately 30 days since discharge from index hospitalization.^21,24,25,29–31,33^ Five^21,24,25,31,33^ studies were randomized trials (1^33^ of which was a cluster-randomized trial), 1^29^ was an interrupted time-series, and 1^30^ was a nonrandomized trial. Individually, no included study showed a significant reduction in 30-day ED use relative to usual care control. Based on the meta-analysis of the 5 RCTs encompassing 3,054 patients, there was no difference in the odds of 30-day ED utilization (OR = 1.03, 95% CI [0.84, 1.27]; 95% PI [0.84, 1.27]) (Figure 2). There was no evidence of statistical heterogeneity across these studies.

Figure 2 Effects of PDC Interventions in First 7 Days on 30-Day ED Use (RCTs Only)

The interrupted time-series trial and the nonrandomized trial also do not show a significant difference in 30-day ED utilization with PDC interventions when compared to usual care. One^24^ study also assessed ED utilization at 90 days with no significant difference in ED utilization with PDC interventions compared to usual care. None of the studies included subgroup analysis on any variable. Details of results by each included study are in the Appendix.

#### Composite Measures of Health Care Utilization

Four studies measured a composite outcome of 30-day unplanned health care utilizations (eg, 30-day hospital readmissions plus ED use or unscheduled office visit). Three^21,24,25^ were randomized trials and 1^30^ was a nonrandomized trial.

Results were consistent with the other 30-day utilization outcomes; individually, these studies showed no impact of PDC on a reduction in 30-day unplanned health care use relative to usual care control. Based on the meta-analysis of the 3 randomized trials encompassing 1,456 patients, there was no significant difference in the odds of 30-day unplanned utilizations (OR = 1.00, 95% CI [0.76, 1.31]; 95% PI [0.76, 1.31]) (Figure 3). Details of these results per study are in the Appendix.

Figure 3 Effects of PDC Interventions in First 7 Days on 30-Day Composite Measures of Health Care Utilization (RCTs Only)

#### Patient Satisfaction

Four RCTs^22,27,28,33^ encompassing 3,397 patients measured some aspects of patient’s satisfaction (eg, clarity of information, overall satisfaction with post-discharge, patient experience with hospital). Overall patient satisfaction with the discharge process was high across control and PDC groups, with only 1 small study (N = 60)^27^ reporting a significantly higher patient satisfaction in the PDC group. Details of these results per study are in the Appendix.

### KQ1b: Impacts by PDC Intervention Characteristics

We explored PDC intervention factors that may have an impact on the outcomes of interest. We found no statistical evidence that the following factors affected the outcomes:

- Mode of PDC (ie, phone vs video)
- Clinical staff initiating the contact (ie, pharmacist vs nurse vs non-clinical staff)
- Timing of the contact (ie, within 3 days vs within 7 days of hospital discharge)
- Use of structured assessments during contact (ie, yes vs no protocolized assessments)
- Content of the contact (ie, containing 1 or more of these core PDC functions: medication review, symptom monitoring, coordination of medical or social services during contact).

Both visual inspection and statistical subgroup testing demonstrated no impact of these characteristics. Forest plots of these subgroup analyses are in the Appendix.

### Certainty of Evidence

The certainty of evidence (COE) was moderate for randomized studies and very low for nonrandomized studies (Table 2). Nine RCTs were graded as moderate COE for no effect of post-discharge contacts on 30-day hospital readmission. This category was downgraded only for imprecision. The 2 observational studies that reported impacts on hospitalization were downgraded to very low certainty for very serious ROB, given serious indirectness as well as imprecision. The evidence for post-discharge contacts on 30-day ED use was rated as moderate COE for no effect and downgraded for imprecision. The 2 observational studies reporting ED use were rated as very low certainty. We did not conduct a GRADE evaluation for the composite outcomes of unplanned health care utilization, though the overall patterns of outcomes were similar to those for hospitalization and ED use.

Table 2 Certainty of Evidence

Outcome | Number of Studies | Findings | Certainty of Evidence (Rationale)
Hospitalization | 9 RCT (7,402 patients) | OR = 0.94 (95% CI [0.83, 1.07]) | Moderate; (Downgraded for imprecision)
Hospitalization | 2 Observational (20,924) | Non-significant results | Very low; (Downgraded for very serious risk of bias, serious indirectness, and imprecision)
Emergency Department Use | 5 RCT (4,724 patients) | OR = 1.03 (95% CI [0.84, 1.27]) | Moderate; (Downgraded for imprecision)
Emergency Department Use | 2 Observational (20,924) | Non-significant results | Very low; (Downgraded for very serious risk of bias, serious indirectness, and imprecision)

Abbreviations. RCT=randomized controlled trial; OR=odds ratio.

## KEY QUESTION 2: EFFECTS OF POST-DISCHARGE CONTACTS AMONG ADULTS WITH ACUTE PSYCHIATRIC HOSPITALIZATIONS

We identified no eligible studies that addressed KQ2a or KQ2b.