# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42023465675 (https://www.crd.york.ac.uk/PROSPERO/display_record.php?RecordID=465675)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were developed with key VHA operational partners:

Key Question 1a | Among adults with acute medical hospital admissions, what are the effects of post-discharge contacts on hospital readmission, emergency care use, and patient satisfaction?
Key Question 1b | Do the effects of post-discharge contacts for acute medical hospital admissions vary by intervention characteristics (ie, mode, clinical staff initiating contact, timing, assessments used during contact, content)?
Key Question 2a | Among adults with acute psychiatric hospital admissions, what are the effects of post-discharge contacts on hospital readmission, emergency care use, and patient satisfaction?
Key Question 2b | Do the effects of post-discharge contacts for acute psychiatric hospital admissions vary by intervention characteristics (ie, mode, clinical staff initiating contact, timing, assessments used during contact)?

Study eligibility criteria are shown in the table below.

Eligibility Criteria
| Inclusion | Exclusion
Population | KQ1: Adults (≥18 years of age) with an acute medical hospital admission; KQ2: Adults (≥18 years of age) with acute psychiatric hospital admission; If populations comprise children and adults and do not include an adult-only subgroup, studies will be included if they have 80% or more adults in the included sample. | - Elective hospitalization; - Obstetric and gynecological hospitalizations; - Discharge from the emergency department (ED); - Discharge from a post-hospitalization inpatient rehabilitation facility, skilled nursing facility, or long-term acute care
Intervention | Post-discharge contact (PDC) is defined as a bidirectional contact (eg, telephone, video, secure messaging system) from a nonspecialist clinical service provider to an adult discharged from inpatient medical or psychiatric hospital that occurs up to 7 days from discharge from a hospitalization and prior to resumption of longitudinal primary care.; A PDC intervention is intended to improve the post-acute transition from hospital to home and include at least 1 of the following components: medication review; coordination of medical or social services; symptom monitoring; or psychoeducation. | Interventions defined primarily as:; - Longitudinal care management (ie, routine care within the 7-day window); - Interventions where the majority of the post-discharge contacts occur outside of the 7-day window; - Telemonitoring; - Passive monitoring; - Health coaching for lifestyle modification; - Programs designed to provide multidisciplinary and longitudinal transitional care that exceeds past 7 days post-discharge from hospital; - Provider-to-provider communications or consultations beyond the initial transfer of information from a patient-initiated contact; - Physician-led communications; - General health education
Comparator | KQ1, KQ2:; - Usual care/standard of care, waitlist control; - Other active comparator (eg, in-person care) | KQ1, KQ2:; - No controls
Outcomes | KQ1, KQ2:; - 30-day hospital readmission; - 30-day emergency care use; - Patient satisfaction | Any outcomes not listed
Setting | Initiated in the inpatient or outpatient setting, if the intent is to provide a post-discharge check-in prior to resumption of longitudinal primary care and there is at least 1 contact made after the patient is discharged | - Any medical setting where the intent is to provide longitudinal management of chronic medical conditions; - Primary care for regular care
Study Design | KQ1, KQ2:; - Randomized trials; - Nonrandomized trials; - Controlled before-after studies; - Interrupted time-series studies or repeated-measures studies that must have more than one measurement before and after intervention implementation | KQ1, KQ2:; - Not a clinical study (eg, editorial, non-systematic reviews, letter to the editor); - Systematic reviews; - Uncontrolled clinical study; - Qualitative studies; - Prospective and retrospective observational studies; - Clinical guidelines; - Measurement or validation studies
Countries | OECD^a^ | Non-OECD
Years | Article published after 2011^b^ | Article published before 2012
Publication Types | Full publication in a peer-reviewed journal | - Letters, editorials, reviews, dissertations, meeting abstracts, protocols without results; - Publications in predatory journals^c^

Notes.

a Organization for Economic Cooperation and Development countries are Australia, Austria, Belgium, Canada, Chile, Colombia, Costa Rica, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Lithuania, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, and United States.

b We constrained our review to studies published after 2011 to account for national policy changes that promoted post-discharge contacts as part of the Patient Protection and Affordable Care Act (ACA). Also, in 2013 Medicare approved procedure codes for transitional care management services consisting of a communication with the patient or caregiver within 2 business days of hospital discharge. We backdated our search 2 years from this date to capture any foundational literature that informed this policy change.

c There is no single way to identify all predatory journals as this is a rapidly evolving industry. Thus, we used the best available guidance to scrutinize potential problematic studies such as pay-to-publish models, lack of rigorous peer-review, rapid publishing timelines, lack of impact factor information, being identified as a potential problematic journal by the field, and expert librarian consultation.

## SEARCHING AND SCREENING

To identify articles relevant to the key questions, a research librarian searched MEDLINE via Ovid, Embase via Elsevier, and CINAHL Complete via EBSCO from 2012 to May 25, 2023, using terms for patient discharge, phone or video, follow-up, readmissions, and ED use (see Appendix for complete search strategies). Editorials, case reports, letters, comments, and conference abstracts were excluded. Additional citations were identified from hand-searching reference lists and consultation with content experts. English-language titles, abstracts, and full-text articles were independently reviewed by 2 investigators, and disagreements were resolved by consensus.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Data from published reports were abstracted into Covidence by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus could not be reached. Data elements included descriptors to assess applicability, quality elements, intervention details, and outcomes (see Appendix for risk of bias [ROB] ratings).

Key characteristics abstracted included participant descriptors (eg, age, sex, race, diagnosis), intervention characteristics (eg, timing, dose, content, interventionist), comparator, and outcomes. To better characterize interventions, and in keeping with emerging standards in systematic reviews with intervention complexity,^14,15^ we mapped each included study to a common set of core functions^16^ (ie, purpose of the change process) of post-discharge interventions: medication review, symptom monitoring, and coordination of social or health services.

We used an adapted Cochrane ROBINS-I tool^17^ to assess risk of bias for nonrandomized studies that compare health effects of 2 or more interventions. The ROBINS-I includes domains for (1) confounding, (2) participant selection, (3) intervention classification, (4) deviations from intended interventions, (5) missing data, (6) outcome measurement, and (7) selective outcome reporting. Overall ROB judgments included low ROB, serious ROB, critical ROB, and no information. For randomized trials, we adapted the Cochrane ROB-2 tool.^18^ This tool includes the following domains: (1) bias arising from the randomization process, (2) bias due to deviations from intended interventions, (3) bias due to missing outcome data, (4) bias in measurement of the outcome, (5) bias in selection of the reported result and has overall ROB as low, some concerns, or high ROB.

## SYNTHESIS

We summarized the primary literature using relevant data abstracted from the eligible studies. Summary tables described the key study characteristics of the primary studies: study design, patient demographics, and details of the intervention and comparator. We then determined the feasibility of completing a quantitative synthesis (ie, meta-analysis) to estimate summary effects.

For meta-analyses, feasibility depends on the volume of relevant literature, conceptual homogeneity of the studies (eg, interventions used, outcomes assessed), and completeness of results reporting. We aggregated outcomes when there were at least 3 studies with the same outcome, based on the rationale that 1 or 2 studies do not provide adequate evidence for summary effects. Dichotomous outcomes were combined using odds ratio and random-effects models as appropriate. We used the Knapp-Hartung approach to adjust the standard errors of the estimated coefficients. We evaluated for statistical heterogeneity using visual inspection and used 95% prediction intervals (PIs). Meta-analyses were conducted using the metafor^19^ package for R (R Foundation for Statistical Computing, Vienna, Austria). If meta-analyses were feasible, we considered subgroup analysis or meta-regression to explore quantitative or qualitative interactions of pre-specified potential effect modifiers deemed important by VA operational partners (eg, clinical staff initiating the contact, intervention content, timing of intervention). As results were consistent across studies, we do not report the findings of these subgroup analyses in keeping with current best approaches in evidence synthesis.

When quantitative synthesis was not feasible, we analyzed the data narratively. We gave more weight to the evidence from higher quality studies with more precise estimates of effect (ie, lower ROB). A narrative synthesis focused on documenting and identifying potential reasons for inconsistency in treatment effects across studies by evaluating differences in the study population, intervention, comparator, and outcome definitions.^2^

### Strength of Evidence

The strength of evidence was assessed using the approach described by Grading of Recommendations Assessment, Development and Evaluation (GRADE).^20^ We limited GRADE ratings to those outcomes identified by the stakeholders and TEP as critical to decision-making. In brief, the GRADE approach required assessment of four domains: risk of bias, consistency, directness, and precision. Additional domains used when appropriate were coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. These domains were considered qualitatively, and a summary rating was assigned after discussion by 2 investigators (JMG, AMG) as high, moderate, low, or very low strength of evidence. In some cases, high, moderate, low, or very low ratings were impossible or imprudent to make. In these situations, a grade of insufficient was assigned.