# BACKGROUND

The time following hospital discharge is recognized as a vulnerable period for patients and is associated with increased morbidity, high incidence of adverse events, and unplanned health care utilizations.^1,2^ Hospital readmissions in the United States remain a common occurrence in the period immediately following a hospital stay. Fingar et al^3^ found that 14% of hospital discharges were readmitted within 30 days and 5% of hospital discharges were readmitted within a week. Other studies show even higher 30-day readmissions rates of 22%, with 8.5% of these readmissions identified as avoidable.^4^ Overall, costs for these readmissions are substantial for health systems and payers, with more than $52.4 billion spent annually caring for patients readmitted within 30 days of discharge for a previously treated diagnosis.^5^ Emergency department (ED) visits also are a common occurrence post-hospitalization, with about 1 in 5 patients using the ED in the 30 days following a hospital discharge.^6^

Over the past decade, there has been an increased focus on transitional care from hospital to home. Procedures to improve pre-discharge planning from hospitals have resulted in small but meaningful reductions in hospital readmissions.^7^ Yet, once back at home, patients may experience uncertainty about how to best care for themselves despite pre-discharge efforts, leading to complications and unplanned health care use. These post-discharge complications commonly stem from poor patient and health care team communication of unresolved problems, lack of patient education regarding medications and treatments, limited monitoring of medication adherence, and delayed monitoring of patient status soon after discharge.^1^ Patients who experience post-discharge complications are at high risk of hospital readmission, an undesired and costly outcome for both patients and health care systems.^8^

In 2012, the Affordable Care Act led to the establishment of the Hospital Readmissions Program from the Centers for Medicare and Medicaid Services (CMS), which created penalties for hospitals with higher 30-day readmission rates for 6 core populations: patients with acute myocardial infarction, congestive heart failure, chronic obstructive pulmonary disease, pneumonia, coronary artery bypass graft, and total hip or knee replacements.^9^ In 2013, CMS subsequently expanded outpatient billing opportunities with new transitional care management (TCM) billing codes to promote timely outpatient follow-up with primary care and, subsequently, to improve outcomes.^9^ Criteria for TCM billing included a face-to-face visit within 7–14 days and communication (direct contact, telephone, or electronic) with patients and/or their caregiver within 2 business days of hospital discharge.^10^

In an effort to reduce hospital readmissions, lower health care costs, and improve patient satisfaction, various multifaceted care models have been developed to improve pre- and post-discharge transitional care, and the Agency for Healthcare Research and Quality recommended implementation of a discharge process toolkit with the majority of steps focusing on pre-discharge planning based on Project RED (Re-Engineered Discharge).^8,11,12^ These multistep programs are designed to optimize the transition process by standardizing core functions of pre-discharge practices such as medication review, patient and caregiver education, coordination of post-discharge care, and education about self-management.^8^ Although some of these models have included a post-discharge component, there is limited information available to assess the direct impact of post-discharge patient contacts that include similar core functions of medication review, symptom monitoring, and coordination of medical or social services in the first week after leaving the hospital on key patient and health system outcomes.

The Veterans Health Administration (VHA) is the largest integrated health system in the nation, serving over 9 million Veterans at 1,321 health care facilities.^13^ Veterans seeking care through the VHA experience a broad variety of medical and psychiatric illnesses that lead to hospital admissions. Currently, there is no standard post-discharge practice for Veteran patients transitioning back home from VHA hospitals. The VHA requires that primary care Patient Aligned Care Teams (PACTs) contact patients 2 days after a hospital discharge and 7 days post-discharge for mental health teams; however, there is variability in implementation across the VHA health care system. To assist the VHA in standardizing post-discharge follow-up contacts, the VHA Office of Primary Care requested this review to assess the impact of post-discharge patient contacts on emergency care use, hospital readmission rates, and patient satisfaction to ensure that effective transitional care is provided to Veterans seeking care through the VHA.