# Appendix

## SEARCH STRATEGIES

Librarian searcher: Sarah Cantrell, MLIS; Duke University Medical Center Library & Archives; Duke University School of Medicine.

Peer review of search conducted by: Samantha Kaplan, PhD, MLIS; Duke University Medical Center Library & Archives; Duke University School of Medicine.

### Database: MEDLINE (via Ovid)

Search date: 5/26/2023

Note: Ovid MEDLINE ALL 1946 to May 25, 2023

| Search Set | Search Statement | Results
1 | Patient discharge | exp patient discharge/ or (postdischarg* or post-discharg*).ti,ab. or ((patient or patients or inpatient or inpatients or in-patient or in-patients or hospital*) adj3 discharg*).ti,ab. or ((post or after) adj2 hospital*).ti,ab. | 161588
2 | Phone or video | telephone/ or cell phone/ or smartphone/ or videoconferencing/ or remote consultation/ or exp text message/ or (phone or phones or phoned or phoning or telephon* or tele-phon* or cellphon* or cell-phon* or smartphon* or smart-phon* or videoconferenc* or video-conferenc* or webconferenc* or web-conferenc* or webex or zoom or skype or FaceTime or GoToMeeting or web-delivered or "web delivered" or internet-delivered or "internet delivered" or computer-delivered or "computer delivered" or teleconsult* or tele-consult* or "remote consult" or "remote consults" or "remote consultation" or "remote consultations" or "remote consulting" or "electronic consult" or "electronic consults" or "electronic consultation" or "electronic consultations" or "electronic consulting" or tele-consult* or teleconsult* or teleconferenc* or teleconferenc* or "text message" or "text messages" or "text messaging").ti,ab. or ((followup or follow-up) adj3 (call or calls or called or calling or text or texts or texting or message or messages or messaging)).ti,ab. or ((remote* or video* or internet or internet-based or web or web-based or online or online-based or computer or computer-based or asynchronous*) adj3 (meet* or call* or chat* or conferenc* or consult* or counsel* or visit* or message or messages or messaging or messaged or text or texts or texting or texted)).ti,ab. or ((video* or remote* or web-based or internet-based or tele*) adj2 care).ti,ab. or ((secure or secured or EHR or EMR or "electronic health record" or "electronic health records" or "electronic medical record" or "electronic medical records") adj3 (text or texts or texting or message or messages or messaging)).ti,ab. or ((asynchronous* or synchronous*) adj3 communicat*).ti,ab. | 168793
3 | Combining | 1 and 2 | 5577
4 | Follow-Up | (follow-up OR followup OR "follows up" OR "followed up" OR "following up" or "after care" or aftercare).ti,ab. | 1289628
5 | Readmissions | exp Patient Readmission/ OR (readmission* OR re-admission* OR readmit* OR re-admit*).ti,ab. | 53636
6 | ED use | Emergency Service, Hospital/ OR ("emergency department" OR "emergency departments" OR "emergency room" OR "emergency rooms").ti,ab. | 173870
7 | combining | 4 or 5 or 6 | 1487227
8 | Combining | 3 and 7 | 3504
9 | Study Design: EPOC filter or RCTs | exp "Cohort Studies"/ or exp "Longitudinal Studies"/ or exp "Follow-Up Studies"/ or exp "Evaluation Studies as Topic"/ or exp "Controlled Before-After Studies"/ or exp "Interrupted Time Series Analysis"/ or "Randomized Controlled Trial".pt. or "Controlled Clinical Trial".pt. or "Clinical Trial".pt. or "Evaluation Studies".pt. or "Comparative Study".pt. or (randomized or randomised or randomization or randomisation or placebo or randomly or trial or trials or groups or "evaluation study" or "evaluation studies" or "intervention study" or "intervention studies" or cohort or cohorts or longitudinal or longitudinally or prospective or prospectively or "follow up" or follow-up or followup or "comparative study" or "comparative studies" or nonrandom or "non-random" or nonrandomized or "nonrandomized" or nonrandomised or "nonrandomised" or quasi-experiment* or quazi-experiment* or quasiexperiment* or quaziexperiment* or quasirandom* or quazirandom* or quasi-random* or quazi-random* or quasi-control* or quazi-control* or quasicontrol* or quazicontrol*).ti,ab. or (controlled AND study).ti,ab. or ("pre-post" or "pre post" or "posttest" or "post-test" or "post test" or pretest or "pre-test" or "pre test" or "repeated measure" or "repeated measures").ti,ab. or (before AND after).ti,ab. or (before AND during).ti,ab. or ("time series" AND interrupt*).ti,ab. or ("time points" AND (multiple or one or two or three or four or five or six or seven or eight or nine or ten or month or monthly or day or daily or week or weekly or hour or hourly)).ti,ab. | 9516428
10 | study design exclusion | 9 not (case reports or editorial or letter or comment or congress).pt. | 3,363
11 | Remove animal-only | 10 not (exp animals/ not exp humans/) | 3233
12 | Remove case reports, editorials, conference abstracts | 11 not (case reports OR editorial OR letter OR comment OR congress).pt. | 3185
13 | Date Limit 2012-present | Limit 12 to da=20120101-20231231 | 2278

### Database: Embase (via Elsevier)

Search date: 5/26/2023

Note: Search from the Results page

| Search Set | Search Statement | Results
1 | Patient discharge | 'hospital discharge'/exp OR (postdischarg* OR 'post discharg*'):ti,ab OR ((patient OR patients OR inpatient OR inpatients OR 'in patient' OR 'in patients' OR hospital*) NEAR/3 discharg*):ti,ab OR ((post OR after) NEAR/2 hospital*):ti,ab | 347638
2 | Phone OR video | 'telephone'/exp OR 'mobile phone'/exp OR 'smartphone'/exp OR 'videoconferencing'/exp OR 'teleconsultation'/exp OR 'text message'/exp OR (phone OR phones OR phoned OR phoning OR telephon* OR 'tele phon*' OR cellphon* OR 'cell phon*' OR smartphon* OR 'smart phon*' OR videoconferenc* OR 'video conferenc*' OR webconferenc* OR 'web conferenc*' OR webex OR zoom OR skype OR FaceTime OR GoToMeeting OR 'web delivered' OR 'internet delivered' OR 'computer delivered' OR teleconsult* OR 'tele consult*' OR 'remote consult' OR 'remote consults' OR 'remote consultation' OR 'remote consultations' OR 'remote consulting' OR 'electronic consult' OR 'electronic consults' OR 'electronic consultation' OR 'electronic consultations' OR 'electronic consulting' OR teleconferenc* OR 'tele conferenc*' OR 'text message' OR 'text messages' OR 'text messaging'):ti,ab OR ((followup OR 'follow up') NEAR/3 (call OR calls OR called OR calling OR text OR texts OR texting OR message OR messages OR messaging)):ti,ab OR ((remote* OR video* OR internet OR web OR online OR computer OR asynchronous*) NEAR/3 (meet* OR call* OR chat* OR conferenc* OR consult* OR counsel* OR visit* OR message OR messages OR messaging OR messaged OR text OR texts OR texting OR texted)):ti,ab OR ((video* OR remote* OR 'web based' OR 'internet based' OR tele*) NEAR/2 care):ti,ab OR ((secure OR secured OR EHR OR EMR OR 'electronic health record' OR 'electronic health records' OR 'electronic medical record' OR 'electronic medical records') NEAR/3 (text OR texts OR texting OR message OR messages OR messaging)):ti,ab OR ((asynchronous* OR synchronous*) NEAR/3 communicat*):ti,ab | 255771
3 | combining | #1 AND #2 | 11472
4 | Follow-Up | 'follow up'/exp OR ('follow up' OR followup OR 'follows up' OR 'followed up' OR 'following up' OR aftercare OR "after care"):ti,ab | 2638498
5 | Readmissions | 'hospital readmission'/exp OR (readmission* OR 're admission*' OR readmit* OR 're admit*'):ti,ab | 119876
6 | ED use | 'hospital emergency service'/exp OR ('emergency department' OR 'emergency departments' OR 'emergency room' OR 'emergency rooms'):ti,ab | 229882
7 | combining | #4 OR #5 OR #6 | 2915778
8 | combining | #3 AND #7 | 7679
9 | Study Design: EPOC filter OR RCTs | 'cohort analysis'/exp OR 'longitudinal study'/de OR 'randomized controlled trial'/exp OR 'controlled clinical trial'/exp OR 'single blind procedure'/exp OR 'double blind procedure'/exp OR 'crossover procedure'/exp OR 'crossover procedure':de OR 'double-blind procedure':de OR 'randomized controlled trial':de OR 'single-blind procedure':de OR (random* OR factorial* OR crossover* OR cross NEXT/1 over* OR placebo* OR doubl* NEAR/1 blind* OR singl* NEAR/1 blind* OR assign* OR allocat* OR volunteer*):ti,ab OR ('evaluation study' OR 'evaluation studies' OR 'intervention study' OR 'intervention studies' OR cohort OR cohorts OR longitudinal OR longitudinally OR prospective OR prospectively OR 'follow up' OR follow-up OR followup OR 'comparative study' OR 'comparative studies' OR nonrandom OR 'non-random' OR nonrandomized OR 'non-randomized' OR nonrandomised OR 'non-randomised' OR quasiexperiment* OR quazi-experiment* OR quasiexperiment* OR quaziexperiment* OR quasirandom* OR quazirandom* OR quasirandom* OR quazi-random* OR quasi-control* OR quazi-control* OR quasicontrol* OR quazicontrol*):ti,ab OR (controlled AND study):ti,ab OR ('pre-post' OR 'pre post' OR 'posttest' OR 'post-test' OR 'post test' OR pretest OR 'pre-test' OR 'pre test' OR 'repeated measure' OR 'repeated measures'):ti,ab OR (before AND after):ti,ab OR (before AND during):ti,ab OR ('time series' AND interrupt*):ti,ab OR ('time points' AND (multiple OR one OR two OR three OR four OR five OR six OR seven OR eight OR nine OR ten OR month OR monthly OR day OR daily OR week OR weekly OR hour OR hourly)):ti,ab | 8130677
10 | combining | #8 AND #9 | 6748
11 | Remove animal-only | #10 AND [humans]/lim | 6451
12 | Remove case reports, editorials, conference abstracts | #11 NOT ('case report'/exp OR 'case study'/exp OR 'editorial'/exp OR [editorial]/lim OR 'letter'/exp OR [letter]/lim OR 'note'/exp OR [note]/lim OR [conference abstract]/lim OR 'conference abstract'/exp OR 'conference abstract'/it) | 3512
13 | Date Limit 2012-present | #12 AND [01-01-2012]/sd | 2520
14 | Exemplar check | #13 AND 31451065:ui | 1/1

### Database: CINAHL Complete (via EBSCO)

Search date: 5/26/2023

| Search Set | Search Statement | Results
1 | Patient discharge | (MH "Patient Discharge") OR (MH "Early Patient Discharge") OR ((TI postdischarg* OR AB postdischarg*) OR (TI post-discharg* OR AB post-discharg*)) OR (((TI patient OR AB patient) OR (TI patients OR AB patients) OR (TI inpatient OR AB inpatient) OR (TI inpatients OR AB inpatients) OR (TI in-patient OR AB in-patient) OR (TI in-patients OR AB in-patients) OR (Ti hospital* OR AB hospital*)) N3 (TI discharg* OR AB discharg*)) OR (((TI post OR AB post) OR (TI after OR AB after)) N2 (TI hospital* OR AB hospital*)) | 74682
2 | Phone or video | (MH "Telephone") OR (MH "Cellular Phone") OR (MH "Text Messaging") OR (MH "Smartphone") OR (MH "Videoconferencing") OR (MH "Teleconferencing") OR (MH "Remote Consultation") OR ((TI phone OR AB phone) OR (TI phones OR AB phones) OR (TI phoned OR AB phoned) OR (TI phoning OR AB phoning) OR (TI telephon* OR AB telephon*) OR (TI tele-phon* OR AB tele-phon*) OR (TI cellphon* OR AB cellphon*) OR (TI cell-phon* OR AB cell-phon*) OR (TI smartphon* OR AB smart-phon*) OR (TI smartphon* OR AB smartphon*) OR (TI video-conferenc* OR AB videoconferenc*) OR (TI video-conferenc* OR AB video-conferenc*) OR (TI webconferenc* OR AB webconferenc*) OR (TI web-conferenc* OR AB web-conferenc*) OR (TI webex OR AB webex) OR (TI zoom OR AB zoom) OR (TI skype OR AB skype) OR (TI FaceTime OR AB FaceTime) OR (TI GoToMeeting OR AB GoToMeeting) OR (TI web-delivered OR AB web-delivered) OR (TI "web delivered" OR AB "web delivered") OR (TI internet-delivered OR AB internet-delivered) OR (TI "internet delivered" OR AB "internet delivered") OR (TI computer-delivered OR AB computer-delivered) OR (TI "computer delivered" OR AB "computer delivered") OR (TI teleconsult* OR AB teleconsult*) OR (TI teleconsult* OR AB tele-consult*) OR (TI "remote consult" OR AB "remote consult") OR (TI "remote consults" OR AB "remote consults") OR (TI "remote consultation" OR AB "remote consultation") OR (TI "remote consultations" OR AB "remote consultations") OR (TI "remote consulting" OR AB "remote consulting") OR (TI "electronic consult" OR AB "electronic consult") OR (TI "electronic consults" OR AB "electronic consults") OR (TI "electronic consultation" OR AB "electronic consultation") OR (TI "electronic consultations" OR AB "electronic consultations") OR (TI "electronic consulting" OR AB "electronic consulting") OR (TI tele-consult* OR AB tele-consult*) OR (TI teleconsult* OR AB teleconsult*) OR (TI teleconferenc* OR AB teleconferenc*) OR (TI tele-conferenc* OR AB tele-conferenc*) OR (TI "text message" OR AB "text message") OR (TI "text messages" OR AB "text messages") OR (TI "text messaging" OR AB "text messaging")) OR (((TI followup OR AB followup) OR (TI follow-up OR AB follow-up)) N3 ((TI call OR AB call) OR (TI calls OR AB calls) OR (TI called OR AB called) OR (TI calling OR AB calling) OR (TI text OR AB text) OR (TI texts OR AB texts) OR (TI texting OR AB texting) OR (TI message OR AB message) OR (TI messages OR AB messages) OR (TI messaging OR AB messaging))) OR (((TI remote* OR AB remote*) OR (TI video* OR AB video*) OR (TI internet OR AB internet) OR (TI internet-based OR AB internet-based) OR (TI web OR AB web) OR (TI web-based OR AB web-based) OR (TI online OR AB online) OR (TI online-based OR AB online-based) OR (TI computer OR AB computer) OR (TI computer-based OR AB computer-based) OR (TI asynchronous* OR AB asynchronous*)) N3 ((TI meet* OR AB meet*) OR (TI call* OR AB call*) OR (TI chat* OR AB chat*) OR (TI conferenc* OR AB conferenc*) OR (TI consult* OR AB consult*) OR (TI counsel* OR AB counsel*) OR (TI visit* OR AB visit*) OR (TI message OR AB message) OR (TI messages OR AB messages) OR (TI messaging OR AB messaging) OR (TI messaged OR AB messaged) OR (TI text OR AB text) OR (TI texts OR AB texts) OR (TI texting OR AB texting) OR (TI texted OR AB texted))) OR (((TI video* OR AB video*) OR (TI remote* OR AB remote*) OR (TI web-based OR AB web-based) OR (TI internet-based OR AB internet-based) OR (TI tele* OR AB tele*)) N2 (TI care OR AB care)) OR (((TI secure OR AB secure) OR (TI secured OR AB secured) OR (TI EHR OR AB EHR) OR (TI EMR OR AB EMR) OR (TI "electronic health record" OR AB "electronic health record") OR (TI "electronic health records" OR AB "electronic health records") OR (TI "electronic medical record" OR AB "electronic medical record") OR (TI "electronic medical records" OR AB "electronic medical records")) N3 ((TI text OR AB text) OR (TI texts OR AB texts) OR (TI texting OR AB texting) OR (TI message OR AB message) OR (TI messages OR AB messages) OR (TI messaging OR AB messaging))) OR (((TI asynchronous* OR AB asynchronous*) OR (TI synchronous* OR AB synchronous*)) N3 (TI communicat* OR AB communicat*)) | 97395
3 | Combining | S1 AND S2 | 3701
4 | Follow-Up | (MH "After Care") OR ((TI follow-up OR AB follow-up) OR (TI followup OR AB followup) OR (TI "follows up" OR AB "follows up") OR (TI "followed up" OR AB "followed up") OR (TI "following up" OR AB "following up") OR (TI "after care" OR AB "after care") OR (TI aftercare OR AB aftercare)) | 348945
5 | Readmissions | (MH "Readmission") OR ((TI readmission* OR AB readmission*) OR (TI re-admission* OR AB re-admission*) OR (TI readmit* OR AB readmit*) OR (TI re-admit* OR AB re-admit*)) | 27971
6 | ED use | (MH "Emergency Service") OR ((TI "emergency department" OR AB "emergency department") OR (TI "emergency departments" OR AB "emergency departments") OR (TI "emergency room" OR AB "emergency room") OR (TI "emergency rooms" OR AB "emergency rooms")) | 103921
7 | combining | S4 OR S5 OR S6 | 466385
8 | combining | S3 AND S7 | 2322
9 | Study Design: EPOC filter or RCTs | (ZT "randomized controlled trial") OR (MH "Randomized Controlled Trials") OR (MH "Double-Blind Studies") OR (MH "Prospective Studies+") OR (MH "Single-Blind Studies") OR (MH "Triple-Blind Studies") OR (MH "Crossover Design") OR (MH "Experimental Studies") OR (MH "Clinical Trials") OR (MH "Intervention Trials") OR (MH "Preventive Trials") OR (MH "Therapeutic Trials+") OR (MH "Controlled Before-After Studies") OR (MH "Interrupted Time Series Analysis") OR (MH "Nonrandomized Trials") OR (MH "Quasi-Experimental Studies+") OR (MH "Multiple Time Series") OR (MH "Time Series") OR (MH "Repeated Measures") OR ((TI randomized OR AB randomized) OR (TI randomised OR AB randomised) OR (TI randomization OR AB randomization) OR (TI randomisation OR AB randomisation) OR (TI placebo OR AB placebo) OR (TI randomly OR AB randomly) OR (TI trial OR AB trial) OR (TI trials OR AB trials) OR (TI groups OR AB groups) OR (TI "evaluation study" OR AB "evaluation study") OR (TI "evaluation studies" OR AB "evaluation studies") OR (TI "intervention study" OR AB "intervention study") OR (TI "intervention studies" OR AB "intervention studies") OR (TI cohort OR AB cohort) OR (TI cohorts OR AB cohorts) OR (TI longitudinal OR AB longitudinal) OR (TI longitudinally OR AB longitudinally) OR (TI prospective OR AB prospective) OR (TI prospectively OR AB prospectively) OR (TI "follow up" OR AB "follow up") OR (TI follow-up OR AB follow-up) OR (TI followup OR AB followup) OR (TI "comparative study" OR AB "comparative study") OR (TI "comparative studies" OR AB "comparative studies") OR (TI nonrandom OR AB nonrandom) OR (TI non-random OR AB non-random) OR (TI nonrandomized OR AB nonrandomized) OR (TI non-randomized OR AB non-randomized) OR (TI nonrandomised OR AB nonrandomised) OR (TI non-randomised OR AB non-randomised) OR (TI quasiexperiment* OR AB quasi-experiment*) OR (TI quazi-experiment* OR AB quazi-experiment*) OR (TI quasiexperiment* OR AB quasiexperiment*) OR (TI quaziexperiment* OR AB quaziexperiment*) OR (TI quasirandom* OR AB quasirandom*) OR (TI quazirandom* OR AB quazirandom*) OR (TI quasi-random* OR AB quasi-random*) OR (TI quazi-random* OR AB quazi-random*) OR (TI quasi-control* OR AB quasi-control*) OR (TI quazi-control* OR AB quazi-control*) OR (TI quasicontrol* OR AB quasicontrol*) OR (TI quazicontrol* OR AB quazicontrol*)) OR ((TI controlled OR AB controlled) AND (TI study OR AB study)) OR ((TI pre-post OR AB pre-post) OR (TI "pre post" OR AB "pre post") OR (TI posttest OR AB posttest) OR (TI post-test OR AB post-test) OR (TI "post test" OR AB "post test") OR (TI pretest OR AB pretest) OR (TI pre-test OR AB pre-test) OR (TI "pre test" OR AB "pre test") OR (TI "repeated measure" OR AB "repeated measure") OR (TI "repeated measures" OR AB "repeated measures")) OR ((TI before OR AB before) AND (TI after OR AB after)) OR ((TI before OR AB before) AND (TI during OR AB during)) OR ((TI "time series" OR AB "time series") AND (TI interrupt* OR AB interrupt*)) OR ((TI "time points" OR AB "time points") AND ((TI multiple OR AB multiple) OR (TI one OR AB one) OR (TI two OR AB two) OR (TI three OR AB three) OR (TI four OR AB four) OR (TI five OR AB five) OR (TI six OR AB six) OR (TI seven OR AB seven) OR (TI eight OR AB eight) OR (TI nine OR AB nine) OR (TI ten OR AB ten) OR (TI month OR AB month) OR (TI monthly OR AB monthly) OR (TI day OR AB day) OR (TI daily OR AB daily) OR (TI week OR AB week) OR (TI weekly OR AB weekly) OR (TI hour OR AB hour) OR (TI hourly OR AB hourly))) | 2152369
10 | Combining | S8AND S9 | 2047
11 | Remove animal-only | S10 NOT (((MH "Animals+") OR (MH "Animal Studies") OR (TI "animal model*")) NOT (MH "human")) | 2046
12 | Remove case reports, editorials, conference abstracts | S11 NOT PT ( Abstract OR Algorithm OR Anecdote OR Bibliography OR Biography OR Book OR Book Chapter OR Book Review OR Cartoon OR Case Study OR Commentary OR Editorial OR Letter OR Masters Thesis OR Doctoral Dissertation OR Forms OR Games OR Pamphlet OR Pamphlet Chapter OR Poetry ) | 1800
13 | Date Limit 2012-present | Published Date: 20120101-20231231 | 1267

## STUDY CHARACTERISTICS

For full study citations, refer to the main report’s reference list.

Study Country Sample Size Design | Population % Female % White | Pre- and Post-Discharge Intervention Description Comparator | Outcome (Time Point) Risk of Bias Rating
Bell, 2016^21^; United States; 851; Randomized trial | Patients aged 18 that were hospitalized for acute coronary syndromes (ACS) and/or acute decompensated heart failure (ADHF), as determined by medical record review conducted by a physician using standard criteria; -Percentage not reported; -Percentage not reported | Pharmacists reconciled preadmission medications and discharge medications with the patient and reported any inconsistencies to the medical team, prior to hospital discharge. The pharmacist then provided tailored counseling, including assessing patient understanding of the medication regimen, barriers to medication adherence, and troubleshooting barriers while the patient was in the hospital. At discharge, the pharmacist provided additional counseling, an illustrated medication schedule showing the discharge regimen, and a pillbox, which the patient practiced filling. The pharmacist employed a teach-back technique to ensure patient understanding. Within 4 days after hospital discharge, study coordinators contacted the patients and inquired about general health, symptoms, and any medication related problems such as regimen confusion, non-adherence, or side effects. If issues were detected, the study coordinator contacted the pharmacist to provide those patients reinforcement education and to resolve problems.; -Usual care/routine discharge | Emergency Department visit; (30 days); Hospital readmission; (30 days); ROB rating: Low
Clari, 2015^22^; Italy; 219; Randomized trial | Patients between 18 and 80 years old hospitalized for elective "low- or medium-intensity orthopaedic surgery" (ASA score < 3); -46% female; -Percentage not reported | Patients assigned to the intervention group received routine care and instruction for discharge. A follow-up telephone call carried out by a nurse who specialised in orthopaedics 24 – 96 hours after discharge that was designed to give the nurse the opportunity to assess the overall health of the patient. During this phone call, the nurse followed a standardized sequence of questions and was also able to record whether or not an educational intervention or reinforcement technique was carried out.; -Usual care/routine discharge | Patient satisfaction; ROB rating: Some concerns
Danielsen, 2020^23^; Norway; 282; Randomized trial | Patients aged 18 and older assigned to the following aortic valve replacement (AVR) treatments: First-time isolated AVR, AVR with concomitant coronary artery bypass grafting (CABG), or AVR with concomitant supra-coronary tube graft (SCG).; -Percentage not reported; -Percentage not reported | Prior to discharge, the intervention group received standard discharge care, which included a scheduled consultation with the treating surgenon before discharge from the tertiary hospital. Project coordinator called intervention patients on day 2 and day 9 after hospital discharge to home (telephone follow-up). These were structured telephone calls comprising of advice on the importance of physical activity in the early rehabilitation phase after AVR, and remindning participant about the availability of 24/7-telephone support to answer questions they might have about their present health condition (patient-centered instructions and/or reassurance). The patients could also call a 24/7-phone hotline that was staffed by a group of dedicated and experienced advanced nurse practitioners to receive information whenever they wanted during the first 30 days after discharge.; -Usual discharge care | Hospital readmissions; (30 days); ROB rating: Some concerns
Farris,2014^24^; United States; 630; Randomized trial | Patients 18 years or older admitted with diagnosis of hypertension, hyperlipidemia, heart failure, coronary artery disease, myocardial infarction, stroke, transient ischemic attack, asthma, chronic obstructive pulmonary disease or receiving oral anticoagulation.; -Percentage not reported; -91.4% White | Minimal Intervention Group:; - Pharmacist case manager (PCM) verifies admission medications with community pharmacy, in addition to medication review by unit pharmacist.; - PCM makes recommendations to inpatient medical team. PCM educates patient during hospitalization, provides discharge medication counseling and wallet card medication list. Strategies are reviewed to enhance self-management.; - No call.; Enhanced Intervention Group:; In addition to PCM activities described for Minimal Intervention Group, the Enhanced group also receives the following after unblinding to PCM at discharge. 1) PCM creates discharge care plan and faxes to community physician and pharmacy.; 2) PCM phones patient 3–5 days post-discharge to evaluate adherence and new side effects and answer questions. Report is faxed to community physician and pharmacist if problem noted.; Control/Usual Care Group:; - Unit pharmacist performs medication review.; - Unit nurse provides discharge summary and medication list. | Hospital readmission; (30 days and 90 days); Emergency Department visit; (30 days and 90 days); ROB rating: Low
Haag,2016^25^; United States; 25; RCT | Independent living elderly adults, age 60 or older, enrolled in care transitions program (CTP) who were at high risk for an emergency department visit or hospital readmission.; -Percentage not reported; -Percentage not reported | A medication therapy management consultation by pharmacist between 3 days and up to 7 business days after hospital discharge. Pharmacist reviewed EMR to complete a comprehensive review of all prescriptions, nonprescriptions, and herbal meds. This review included the identification, resolution, and prevention of drug related problems including adverse events or the use of inappropriate medication.; -Usual care group: a nurse practioner home visit within 3 days after discharge to review medication. | Emergency Department visits; (30 days); Hospital readmissions; (30 days); Composite of both Emergency Department visits and hospital readmissions; (30 days); ROB rating: Some concerns
Lee,2020^26^; United States; 2372; RCT | All patients aged ≥ 21 years who were hospitalized in 16 hospitals between January 15, 2017, and March 31, 2018, within Kaiser Permanente Northern California with heart failure (HF); identified by diagnosis codes for HF as the primary hospital problem, or diagnosis code for a HF-related sign or symptom as the primary hospital problem in combination with a HF-specific diagnosis code as a secondary problem; -44% female; -60.4% White | Telephone appointment - patients were called by a nurse or pharmacist who were previously trained and experienced using a structure HF protocol, including directions for titrating diuretics and other HF-related medications and ordering lab tests based on reported symptoms and vitals. Nurse/pharmacist also had immediate access to supervising physician and could arrange for expedited appointments as necessary.; -In-person clinic appointment (usual care) - scheduled primarily with their primary care physician who provided usual care | Hospital readmission for heart failure; (30 days); Hospital readmission for ay cause; (30 days); ROB rating: Some concerns
Lindpaintner, 2013^27^; Switzerland; 60; RCT | Patients were “high risk” for adverse events after discharge and had either: oral anticoagulation, newly ordered insulin, polypharmacy (defined as more than eight regularly used medicines at the time of admission), or new diagnosis requiring four or more long-term medicines.; Patients also either lived alone, received home nursing care prior to admission, or required complex wound care.; -50% female; -Percentage not reported | For patients in the intervention group, prior to discharge the nurse care manager (NCM) conducted a comprehensive structured assessment of symptom burden, prior adherence to prescribed therapies, family caregiving, functional status using the Barthel Index, cognition using a German adaptation of the Mini Mental Test and the Clock-drawing Test, and comorbidity, using the Charlson Comorbidity Index (CCI). The NCM then conferred with the ward team about discharge planning and joined the team for rounds on intervention patients. Contacting patients by structured telephone contact within 24 hours of discharge, evaluating selfefficacy and giving reminders about self-management strategies and follow-up appointments; Availability of the NCM by pager 24/7 for 5 days following discharge; Ending the intervention with a home visit and a letter to the primary care physician; Using proprietary case management software (e-case) adapted for the project to collect data and generate correspondence. The individualized interventions emphasized adherence, self-management skills, and extending the network of support available to patient and family caregivers.; -Usual care/routine discharge | Hospital readmission; (30 days); ROB rating: Some concerns
Lundby,2020^28^; Denmark; 64; RCT | Patients 18 years or older discharged from the gastrointestinal unit with gastrointestinal diseases (inflammatory bowel disease, cancer within the gastrointestinal system, or complex fistulas); -48% female; -Percentage not reported | Intervention included preparing patient information for the discharge counseling, medication review, discussion with physician, patient counseling at discharge, medication report to primary care physician, and phone follow-up to the patient 3 days after discharge. The discharge counseling included an updated medication list and a written summary of the counseling for the patient to take home, including a direct phone number to the pharmaconomist performing the counseling. | Patient satisfaction; ROB rating: High
Robinson,2015^29^; New Zealand; 20682; Interrupted time-series | Age 65 years with an acute medical admission that were identified as being “high risk” patients; -Percentage not reported; -Percentage not reported | Pre-discharge component: nutrition screening, and if necessary referral to a dietitian; allied health review; and discharge medicines reconciliation and patient education by a pharmacist. Post-discharge component: a telephone assessment, education, and support by a team of experienced community nurses on the first and third days post-discharge.; No comparator | Hospital readmission; (28 days); Emergency Department visit; (28 days); ROB rating: Serious
Sarangarm,2013^30^; United States; 279; Nonrandomized trial | All English- or Spanish-speaking patients who were discharged from all internal medicine teams between 8 am and 5 pm Monday through Friday were included in the study based on pharmacist availability to perform discharge counseling; -44% female; -89% White | Intervention patients received discharge counseling from a pharmacist that included information about proper medication administration, side effects, and disease state education. Pharmacists also reviewed patients' medications and prescriptions by completing medication review; identifying duplicative, unnecessary, or incomplete therapy; checking for drug interactions; verifying patients' formulary drug coverage and availability of medications; and ensuring prescription completeness. To minimize interpharmacist variability during the discharge process, a standardized checklist was developed outlining the topics to be covered during a counseling session, and standardized patient education leaflets were used.; Usual discharge care | Composite hospital readmissions and Emergency Department visits; (30 days); ROB rating: Serious
Soong,2014^31^; Canada; 334; Cluster RCT | General medical patients age 18 and older discharged home after hospitalization; -Percentage not reported; -Percentage not reported | The discharge process involves each patient receiving a copy of the electronic discharge summary and patient-specific instructions. In addition, the provider must review written discharge instructions with the patient and/or caregiver. The non-clinicical pateint navigator called a patient or caregiver within 3 days following discharge from hospital with a minimum of 5 attempts conducted. A standardized intervention phone script that solicited information on general health status post discharge, comprehension of discharge instructions, and reinforced instructions was read to the patient. The caller utilized a modified teach-back method to educate the patient on discharge instructions, medications, and follow up recommendations.; Usual care | Emergency Department visit; (30 days); Hospital readmission; (30 days); ROB Rating: Some concerns
Sorknaes,2013^32^; Denmark; 266; RCT | Patients who were at least 40 years old and 1) diagnosed with COPD verified by spirometry; 2) admitted with acute exacerbation of COPD (AECOPD) "defined by increased need or medicine and increased dyspnoea, increased expectorate volume or increased coughing"; -Percentage not reported; -Percentage not reported | All COPD patients admitted with exacerbation received conventional treatment according to GOLD guidelines, ie, inhaler with bronchodilator medication, systemic glucocorticoid treatment, and if needed, antibiotics, noninvasive ventilation or respirator treatment. Prior to discharge, control of inhalation techniques was performed and a decision was made concerning the treatment with which the patient should continue.Intervention consisted of daily teleconsultations (initiated within 24 hours of discharge) conducted by a nurse via videom everyday for an average of 7 days post-dsicharge. Telemedicine equipment loaned to patient at discharge allowed patient to measure pulse, oxygen saturation, and spirometry and transmit the information to the nursing providing the intervention. The week after the teleconsultations were finished, a telephone follow-up call was made.; Conventional treatment | Hospital readmissions (within 26 weeks); ROB rating: Some concerns
Yiadom,2020^33^; United States; 3054; RCT | All inpatients discharged home from a general medicine service; -Percentage not reported; -Percentage not reported | A semi structured script was used to guide the conversation to assess their knowledge of discharge diagnosis and plan, with attention to medication changes, follow-up appointments, and anticipated discharge support services (medication procurement, visiting health assistance, and needed equipment). Patients were asked to “teach back” their discharge plan. Gaps in knowledge or planned care transition supports were identified and addressed as needed. | Hospital readmission; (30 days); ROB rating: Low

## INTERVENTION CHARACTERISTICS

For full study citations, refer to the main report’s reference list.

Study | Mode Timing Dose | Staff Access to EHR Assessments Conducted | Post-Discharge Intervention Description | Core Components Outcomes Assessed
Bell, 2016^21^ | Phone; Within 4 days; 1 call | Study coordinator; pharmacist (if needed); Yes; Medication related problems; general health assessment; symptom screener | Within 4 days after hospital discharge, study coordinators contacted the patients and inquired about general health, symptoms, and any medication related problems such as regimen confusion, non-adherence, or side effects. If issues were detected, the study coordinator contacted the pharmacist to provide those patients reinforcement education and to resolve problems. | Medication review, monitoring; Emergency department visits, hospitalizations/readmissions, patient satisfaction/composite outcomes
Clari, 2015^22^ | Phone; Within 4 days; 1 call, 4.89 minutes on average | Nurses; Do not know; Overall health screener; explore experienced and potentail problems via standarized sequence of questions | A follow-up telephone call carried out by a nurse who specialised in orthopaedics 24 – 96 hours after discharge designed to give the nurse the opportunity to assess the overall health of the patient | Medication review, monitoring; Patient satisfaction/composite outcomes
Danielsen,2020^23^ | Phone; Day 2; Number and duration of calls not specified | Study coordinator; pharmacist (if needed); Yes; None | Project coordinator called intervention patients on day 2 and day 9 after hospital discharge to home (telephone follow-up). These were structured telephone calls comprising of advice on the importance of physical activity in the early rehabilitation phase after AVR, and remindning participant about the availability of 24/7 telephone support to answer questions they might have about their present health condition (patient-centered instructions and/or reassurance). The patients could also call a 24/7 phone hotline that was staffed by a group of dedicated and experienced advanced nurse practitioners to receive information whenever they wanted during the first 30 days after discharge. | Coordination of services; Hospitalizations/readmissions
Farris, 2014^24^ | Phone; 3–5 days post-discharge; 1 call; duration not reported | Pharmacist; Do not know; None | Pharmacist case manager (PCM) creates discharge care plan and faxes to community physician and pharmacy.; PCM phones patient 3–5 days post-discharge to evaluate adherence and new side effects and answer questions. Report is faxed to community physician and pharmacist if problem noted. | Medication review, coordination of services, monitoring; Emergency department visits, hospitalizations/readmissions, patient satisfaction/composite outcomes
Haag, 2016^25^ | Phone; 3 days; Number and duration of calls not specified | Pharmacist; study coordinator; Yes; None | A medication therapy management consultation by pharmacist between 3 days and up to 7 business days after hospital discharge. Pharmacist reviewed eMr to complete a comprehensive review of all prescriptions, nonprescriptions, and herbal meds. This review included the identification, resolution, and prevention of drug related problems including adverse events or the use of inappropriate medication. Additionally, the electronic medical record was investigated for potential prescribing omissions. This review was the foundation for the phone consultation with the patient to ensure medication optimization. | Medication review; Emergency department visits, hospitalizations/readmissions, patient satisfaction/composite outcomes
Lee, 2020^26^ | Phone; Within 7 days; 1 call, duration not reported | Pharmacist or nurse; Yes; Symptom management protocol; self-report weight; self-report blood pressure; medication review | Within 7 days post-discharge patients were called by a nurse or pharmacist who were previously trained and experienced using a structured HF protocol, including directions for titrating diuretics and other HF-related medications and ordering lab tests based on reported symptoms and vitals. Nurse/pharmacist also had immediate access to supervising physician and could arrange for expedited appointments as necessary. | Medication review; coordination of services; monitoring; Hospitalizations/readmissions
Lindpaintner, 2013^27^ | Phone; Day 1; 1 call, duration not reported | Nurse (registered nurse with Masters degree); Yes; Medication review | Structured telephone contact within 24 hours of discharge, evaluating self-efficacy and giving reminders about self-management strategies and follow-up appointments and making the Nurse Care manager available to the patient by pager 24/7 for 5 days following discharge. Ending the intervention with a home visit and a letter to the primary care physician. Using proprietary case management software (e-case) adapted for the project to collect data and generate correspondence. | Medication review; coordination of services; Hospitalizations/readmissions
Lundby, 2020^28^ | Phone; Within 3 days; 1 call, mean time intervention + call 32 min (range 25–35) | Pharmaconomist; Do not know; None | Phone follow-up to the patient 3 days after discharge. The discharge counseling included an updated medication list and a written summary of the counseling for the patient to take home, including a direct phone number to the pharmaconomist performing the counseling. | Medication review; Patient satisfaction/composite outcomes
Robinson, 2015^29^ | Phone; Day 1 and 3; 2 calls; duration not reported | Nurse (supported by a geriatrician, a pharmacist, and cultural support workers); Yes; None | A telephone assessment, education, and support by a team of experienced community nurses on the first and third days post-discharge. | Medication review, coordination of services, monitoring; Emergency department visits, hospitalizations/readmissions
Sarangarm, 2013^30^ | Phone; 2–3 days; 1 call; duration not reported | Pharmacist; Yes; None | Intervention patients received a phone call 36 to 72 hours post-discharge to assess patient clinical status and to identify and resolve further medication-related issues. | Medication review; coordination of services; Emergency department visits, hospitalizations/readmissions, patient satisfaction/composite outcomes
Soong, 2014^31^ | Phone; Within 3 days; 1 call | Patient navigator; Yes; General health screener; structured assessment of discharge instructions | Within 3 days following discharge from hospital the PN called a patient or caregiver and a standardized intervention phone script that solicited information on general health status post discharge, comprehension of discharge instructions, and reinforced instructions was read to the patient. The caller utilized a modified teach-back method to educate the patient on discharge instructions, medications and follow up recommendations. | Coordination of services; monitoring; Emergency department visits, hospitalizations/readmissions
Sorknaes, 2013^32^ | Video; Day 1–9; Daily for 5 to 9 days, duration not reported | Nurse; N/A; Pulse, oxygen saturation, and spirometry | Daily teleconsultations post-discharge conducted by a nurse via video. Telemedicine equipment loaned to patient at discharge allowed patient to measure pulse, oxygen saturation, and spirometry and transmit the information to the nursing providing the intervention. | Coordination of services; monitoring; Hospitalizations/readmissions
Yiadom, 2020^33^ | Phone; Within 3 days; Not reported | Not reported; Yes; Structured assessment of understanding of discharge reccommendations | A first call attempt was made within 72 hours of discharge with at least 3 call attempts made until successful contact for up to 7 days after discharge. A semistructured script was used to guide a conversation with the patient to assess their knowledge of their discharge diagnosis and plan with attention to medication changes, follow-up appointments, and actualization of anticipated discharge supports, including acquisition of durable medical equipment, visiting health assistance visits, and medication procurement. Patients were asked to “teach back” their discharge plan. | Medication review; coordination of services; Emergency department visits, patient satisfaction/composite outcomes

## RESULTS: HOSPITAL READMISSIONS

For full study citations, refer to the main report’s reference list.

Study Design | Outcome (Time Point) | Results
Bell, 2016^21^; RCT | Unplanned hospitalizations assessed via follow-up call; (30 days) | PILL-CVD; Events: 61; Total: 423; Usual care; Events: 66; Total: 428; Adjusted hazard ratios: 0.94 (95% CI [0.63, 1.28]); P value = NR
Danielsen, 2020^23^; RCT | All-cause hospital readmission; (30 days) | Telepone follow-up/hotline; Events: 32; Total: 127; Post-discharge usual care; Events: 26; Total: 133; Chi-squared: 1.196; P value = 0.274
Farris, 2014^24^; RCT | Hospital readmission; (30 days) | Enhanced intervention; Events: 47; Total: 287; Minimal intervention; Events: 40; Total: 296; Effect estimate: NR; P value: NR
Farris, 2014^24^; RCT | Hospital readmission; (90 days) | Enhanced intervention; Events: 49; Total: 287; Minimal intervention; Events: 51; Total: 296; Effect estimate: NR; P value = NR
Haag, 2016^25^; RCT | Hospital readmission; (30 days) | Pharmacist intervention; Events: 2; Total: 11; Usual care; Events: 1; Total: 11; Effect estimate: NR; P value = 0.53
Lee, 2020^26^; RCT | Heart failure hospitalizations obtained from EHR; (30 days) | Telephone follow-up; Events: NR; Total: 1027; Usual care (in-person visit in the first 7 days); Events:; Total: 1064; HR = 0.81 (95% CI [0.59, 1.11]); P value = NR
Lee, 2020^26^; RCT | All-cause hospitalizations obtained from EHR; (30 days) | Telephone follow-up; Events: NR; Total: 1027; Usual care (in-person visit in the first 7 days); Events:; Total: 1064; HR = 0.82 (95% CI [0.66, 1.02]); P value = NR
Lindpaintner, 2013^27^; RCT | Readmission reported by patient, visiting nurse, or primary care provider; (5 days) | Discharge management; Events: 1; Total: 28; Usual care; Events: 2; Total: 29; Effect estimate: NR; P value = NR
Lindpaintner, 2013^27^; RCT | Readmission reported by patient, visiting nurse, or primary care provider; (30 days) | Discharge management; Events: NR; Total: 29; Usual care; Events: NR; Total: 30; Effect estimate: NR; P value = 0.026
Robinson, 2015^29^ Interrupted time-series | Pre-intervention period trend (% change per month); (28 days) | Transition of care calls; Events: NR; Total: NR; Pre-intervention; Events: NR; Total: NR; Percent change per month: 0; P value = 0.334
Robinson, 2015^29^ Interrupted time-series | Development period trend (% change per month); (28 days) | Transition of care calls; Events: NR; Total: NR; Pre-intervention; Events: NR; Total: NR; Percent change per month: 0.4; P value = 0.683
Robinson, 2015^29^ Interrupted time-series | Intervention period trend (% change per month); (28 days) | Transition of care calls; Events: NR; Total: NR; Pre-intervention; Events: NR; Total: NR; Percent change per month: −0.6; P value = 0.604
Robinson, 2015^29^ Interrupted time-series | Shift (pre-intervention/development) (%); (28 days) | Transition of care calls; Events: NR; Total: NR; Pre-intervention; Events: NR; Total: NR; Percent change between pre-intervention and development: −1.6; P value = 0.614
Robinson, 2015^29^ Interrupted time-series | Shift (development/intervention) (%); (28 days) | Transition of care calls; Events: NR; Total: NR; Pre-intervention; Events: NR; Total: NR; Percent change between development and intervention: 1.7; P value = 0.502
Sarangarm, 2013^30^; Nonrandomized trial | Total number of post-discharge hospital admissions; (30 days) | Pharmacist counseling; Events: 20; Total: 140; Usual care; Events: 16; Total: 139; Effect estimate: NR; P value = 0.49
Soong, 2014^31^; Cluster RCT | Unplanned hospitalizations (readmission to any hospital in the local health region as verified per patient self-report and/or available electronic medical records); (30 days) | Patient navigator call group; Events: 15; Total: 107; No call group; Events: 13; Total: 107; OR = 1.18 (95% CI [0.53, 2.61]); P value = 0.68
Sorknaes, 2013^32^; RCT | Total readmission after discharge; (182 days) | Teleconsultations; Events: NR; Total: 121; Conventional treatment; Events: NR; Total: 121; Mean difference: 0.14 (95% CI [−0.4, 0.68]); P value = 0.62
Sorknaes, 2013^32^; RCT | Total readmission after discharge; (84 days) | Teleconsultations; Events: NR; Total: 127; Conventional treatment; Events: NR; Total: 126; Mean difference: −0.03 (95% CI [−0.38, 0.32]); P value = 0.87
Sorknaes, 2013^32^; RCT | Total readmission after discharge; (56 days) | Teleconsultations; Events: NR; Total: 127; Conventional treatment; Events: NR; Total: 130; Mean difference: −0.16 (95% CI [−0.44, 0.12]); P value = 0.26
Sorknaes, 2013^32^; RCT | Total readmission after discharge; (28 days) | Teleconsultations; Events: NR; Total: 130; Conventional treatment; Events: NR; Total: 131; Mean difference: −0.08 (95% CI [−0.25, 0.09]); P value = 0.35
Sorknaes, 2013^32^; RCT | AECOPD readmission; (182 days) | Teleconsultations; Events: NR; Total: 121; Conventional treatment; Events: NR; Total: 121; Mean difference: 0.06 (95% CI [−0.43, 0.54]); P value = 0.82
Sorknaes, 2013^32^; RCT | AECOPD readmission; (84 days) | Teleconsultations; Events: NR; Total: 127; Conventional treatment; Events: NR; Total: 126; Mean difference: −0.05 (95% CI [−0.35, 0.25]); P value = 0.75
Sorknaes, 2013^32^; RCT | AECOPD readmission; (56 days) | Teleconsultations; Events: NR; Total: 127; Conventional treatment; Events: NR; Total: 130; Mean difference: −0.16 (95% CI [−0.4, 0.09]); P value = 0.2
Sorknaes, 2013^32^; RCT | AECOPD readmission; (28 days) | Teleconsultations; Events: NR; Total: 130; Conventional treatment; Events: NR; Total: 131; Mean difference: −0.09 (95% CI [−0.25, 0.07]); P value = 0.28
Yiadom, 2020^33^; RCT | Inpatient readmission; (30 days) | Telephone call program; Events: 228; Total: 1534; Usual care; Events: 232; Total: 1520; Absolute difference: −0.4 (95% CI [−2.9, 2.1]); P value = 0.76
Yiadom, 2020^33^; RCT | Observation readmission; (30 days) | Telephone call program; Events: 59; Total: 1534; Usual care; Events: 55; Total: 1520; Absolute difference: 0.2 (95% CI [−1.1, 1.6]); P value = 0.74
Yiadom, 2020^33^; RCT | Any revisit; (30 days) | Telephone call program; Events: 318; Total: 1534; Usual care; Events: 322; Total: 1520; Absolute difference: −0.5 (95% CI [−3.3, 2.4]); P value = 0.76

## RESULTS: EMERGENCY CARE USE

For full study citations, refer to the main report’s reference list.

Study Design | Outcome (Time Point) | Results
Bell, 2016^21^; RCT | Unplanned ED visits assessed via follow-up call; (30 days) | PILL-CVD; Events: 89; Total: 423; Usual care; Events: 85; Total: 428; Adjusted hazard ratios: 1.03 (95% CI [0.76, 1.39]); P value = NR
Haag, 2016^25^; RCT | Emergency department visits; (30 days) | Pharmacist intervention; Events: 1; Total: 11; Usual care; Events: 1; Total: 11; Effect estimate: NR; P value = >0.99
Robinson, 2015^29^; Interrupted time-series | Pre-intervention period trend (% change per month); (28 days) | Transition of care calls; Events: NR; Total: NR; Pre-intervention; Events: NR; Total: NR; Percent change per month: 0.1; P value = 0.1
Robinson, 2015^29^; Interrupted time-series | Development period trend (% change per month); (28 days) | Transition of care calls; Events: NR; Total: NR; Pre-intervention; Events: NR; Total: NR; Percent change per month: −0.7; P value = 0.445
Robinson, 2015^29^; Interrupted time-series | Intervention period trent (% change per month); (28 days) | Transition of care calls; Events: NR; Total: NR; Pre-intervention; Events: NR; Total: NR; Percent change per month: 0.7; P value = 0.478
Robinson, 2015^29^; Interrupted time-series | Shift (pre-intervention/development) (%); (28 days) | Transition of care calls; Events: NR; Total: NR; Pre-intervention; Events: NR; Total: NR; Percent change between pre-intervention and development: 1.5; P value = 0.547
Robinson, 2015^29^; Interrupted time-series | Shift (development/intervention) (%); (28 days) | Transition of care calls; Events: NR; Total: NR; Pre-intervention; Events: NR; Total: NR; Percent change between development and intervention: 3.1; P value = 0.174
Sarangarm, 2013^30^; Nonrandomized | Total number of post-discharge ED visits; (30 days) | Pharmacist counseling; Events: 17; Total: 140; Usual care; Events: 11; Total: 139; Effect estimate: NR; P value = 0.24
Soong, 2014^31^; Cluster RCT | Unplanned ED visits to any hospital in the local health region as verified per patient self-report and/or available electronic medical records; (30 days) | Patient navigator call group; Events: 22; Total: 107; No call group; Events: 19; Total: 107; OR = 1.2 (95% CI [0.61, 2.37]); P value = 0.6
Yiadom, 2020^33^; RCT | Emergency department revisits; (30 days) | Telephone call program; Events: 93; Total: 1534; Usual care; Events: 82; Total: 1520; Absolute difference: 0.7 (95% CI [−1, 2.3]); P value = 0.43
Farris, 2014^24^; RCT | ED visits; (30 days) | Rnhanced intervention; Events: 38; Total: 287; Minimal intervention; Events: 49; Total: 296; Effect estimate: NR; P value = NR
Farris, 2014^24^; RCT | ED visits; (90 days) | Enhanced intervention; Events: 41; Total: 287; Minimal intervention; Events: 40; Total: 296; Effect estimate: NR; P value = NR

## RESULTS: COMPOSITE MEASURES OF UTILIZATION

For full study citations, refer to the main report’s reference list.

Study Design | Outcome (Time Point) | Results
Haag, 2016^25^; RCT | Composite 30-day emergency department visit or hospital readmission; (30 days) | Pharmacist intervention; Events: 2; Total: 11; Usual care; Events: 1; Total: 11; Effect estimate: NR; P value = 0.53
Sarangarm, 2013^30^; Nonrandomized trial | Combined total number of 30-day post-discharge hospitalizations and ED visits; (30 days) | Pharmacist counseling; Events: 30; Total: 140; Usual care; Events: 24; Total: 139; Effect estimate: NR; P value = 0.34
Farris, 2014^24^; RCT | Composite healthcare utilization: composite variable of combined hospital readmission, emergency department visit or unscheduled office visit; (30 days) | Enhanced intervention; Events: 81; Total: 287; Minimal intervention; Events: 88; Total: 296; Effect estimate: NR; P value = NR
Farris, 2014^24^; RCT | Composite healthcare utilization: composite variable of combined hospital readmission, emergency department visit or unscheduled office visit; (90 days) | Enhanced intervention; Events: 97; Total: 287; Minimal intervention; Events: 90; Total: 296; Effect estimate: NR; P value = NR
Bell, 2016^21^; RCT | First unplanned health care utilization; was defined as a composite of first unplanned hospital readmission or ER visit within 30 days after discharge; (30 days) | PILL-CVD; Events: 97; Total: 423; Usual care; Events: 92; Total: 428; Adjusted hazard ratios: 1.04 (95% CI [0.78, 1.39]); P value = NR

## RESULTS: PATIENT SATISFACTION

For full study citations, refer to the main report’s reference list.

Study Design | Outcome (Time Point) | Results
Clari, 2015^22^; RCT | Patients who said the information was useful; (15 days) | Telephone follow-up; Events: NR; Total: NR; Routine care; Events: NR; Total: NR; Effect estimate: NR; P value = 0.004
Clari, 2015^22^; RCT | Overall experience; (15 days) | Telephone follow-up; Events: NR; Total: NR; Routine care; Events: NR; Total: NR; Effect estimate: NR; P value = 0.07
Clari, 2015^22^; RCT | Patients experience with clarity of information; (15 days) | Telephone follow-up; Events: NR; Total: NR; Routine care; Events: NR; Total: NR; Effect estimate: NR; P value = 0.08
Lindpaintner, 2013^27^; RCT | Overall satisfaction with discharge process, 4-point Likert scale; (5 days) | Discharge Management; Events: NA; Total: NA; Usual care; Events: NA; Total: NA; Effect estimate: NR; P value = 0.027
Lindpaintner, 2013^27^; RCT | Overall satisfaction with discharge process, 4-point Likert scale; (30 days) | Discharge management; Events: NA; Total: NA; Usual care; Events: NA; Total: NA; Effect estimate: NR; P value = 0.008
Lundby, 2020^28^; RCT | Overall satisfaction; (7 days) | Medication counseling; Events: 24; Total: 32; Usual care; Events: 29; Total: 32; Effect estimate: NR; P value = 0.1
Lundby, 2020^28^; RCT | Overall satisfaction; (7 days) | Medication counseling; Events: 8; Total: 32; Usual care; Events: 0.09; Total: 32; Effect estimate: NR; P value = NR
Yiadom, 2020^33^; RCT | Patient expereince assessed using 2 items of the Hospital Consumer Assessment of Healthcare Providers and Systems score data from Press Ganey (ie, ovearall satifiacation; likelihood of recommending hosptial; (30 days) | Telephone call program; Events: NA; Total: NA; Usual care; Events: NA; Total: NA; Absolute difference: 16% response rate was too low for analysis; P value = NA

## SUBGROUP ANALYSES

### 30-DAY HOSPITAL READMISSION

### 30-DAY EMERGENCY DEPARTMENT USE

### 30-DAY COMPOSITE ED AND HOSPITAL UTILIZATION

## STUDIES EXCLUDED DURING FULL-TEXT SCREENING

Citation
Abu-Sheasha, 2020^1^ | Ineligible country
Adams, 2020^2^ | Ineligible study design
Ahc, 2018^3^ | Ineligible comparator
Bashir, 2016^4^ | Ineligible study design
Botha, 2018^5^ | Ineligible country
Brearly, 2020^6^ | Ineligible study design
Cawthon, 2012^7^ | Ineligible intervention
Chan, 2015^8^ | Ineligible intervention
Charles, 2020^9^ | Ineligible intervention
Chen, 2019^10^ | Ineligible country
Choudhury, 2022^11^ | Ineligible study design
Christy, 2016^12^ | Ineligible intervention
Costantino, 2013^13^ | Ineligible intervention
Crannage, 2020^14^ | Ineligible study design
Dichmann Sorknaes, 2016^15^ | Ineligible intervention
Donze, 2023^16^ | Ineligible population
Elmose Mols, 2019^17^ | Ineligible outcomes
Fera, 2014^18^ | Ineligible study design
Freburger, 2022^19^ | Ineligible intervention
Gaines-Dillard, 2015^20^ | Ineligible study design
Gamez-Lopez, 2012^21^ | Ineligible intervention
Gesell, 2019^22^ | Ineligible outcomes
Goldman, 2014^23^ | Ineligible intervention
Hamar, 2016^24^ | Ineligible intervention
Hamar, 2018^25^ | Ineligible study design
Hani, 2021^26^ | Ineligible country
Hervieu-Begue, 2013^27^ | Ineligible study design
Hodalova, 2020^28^ | Ineligible intervention
Hoyer, 2018^29^ | Ineligible study design
Iacoviello, 2017^30^ | Ineligible intervention
Irewall, 2019^31^ | Ineligible outcomes
Jahn, 2014^32^ | Ineligible outcomes
Jalal, 2016^33^ | Ineligible population
Jennings, 2015^34^ | Ineligible intervention
Jenq, 2016^35^ | Ineligible intervention
Jones, 2018^36^ | Ineligible study design
Kansagara, 2012^37^ | Ineligible study design
Kassymova, 2021^38^ | Ineligible population
Kassymova, 2023^39^ | Ineligible population
Kilcup, 2013^40^ | Ineligible study design
Kirkham, 2014^41^ | Ineligible study design
Kripalani, 2019^42^ | Ineligible study design
Lavesen, 2016^43^ | Ineligible intervention
Lee, 2022^44^ | Ineligible population
Lindegaard Pedersen, 2017^45^ | Ineligible intervention
Lisby, 2019^46^ | Ineligible population
Liu, 2013^47^ | Ineligible country
Löser, 2022^48^ | Ineligible population
March, 2022^49^ | Ineligible study design
Marcus, 2018^50^ | Ineligible study design
Matarazzo, 2019^51^ | Ineligible outcomes
Miller, 2015^52^ | Ineligible study design
Miller, 2016^53^ | Ineligible study design
Monkong, 2020^54^ | Ineligible country
Montero, 2016^55^ | Ineligible study design
Nguyen, 2023^56^ | Ineligible study design
Nguyen, 2018^57^ | Ineligible intervention
Noel, 2020^58^ | Ineligible intervention
O’Reilly, 2020^59^ | Ineligible study design
Odeh, 2019^60^ | Ineligible study design
Ota, 2013^61^ | Ineligible study design
Parodi, 2022^62^ | Ineligible study design
Phatak, 2016^63^ | Ineligible intervention
Phillip, 2022^64^ | Ineligible publication type
Rasmussen, 2023^65^ | Ineligible study design
Rice, 2016^66^ | Ineligible study design
Rinfret, 2013^67^ | Ineligible outcomes
Ritchie, 2016^68^ | Ineligible intervention
Ross, 2017^69^ | Ineligible intervention
Salmany, 2018^70^ | Ineligible country
Seto, 2020^71^ | Ineligible publication type
Shah, 2021^72^ | Ineligible population
Shalaby, 2022^73^ | Ineligible intervention
Shaver, 2019^74^ | Ineligible study design
Shepherd, 2015^75^ | Ineligible intervention
Sides, 2012^76^ | Ineligible intervention
Simpson, 2014^77^ | Ineligible intervention
Smith, 2021^78^ | Ineligible intervention
Sutton, 2021^79^ | Ineligible outcomes
Szöts, 2016^80^ | Ineligible intervention
Tedesco, 2016^81^ | Ineligible study design
Trang, 2015^82^ | Ineligible study design
Turan Kavradim, 2020^83^ | Ineligible outcomes
Tuso, 2013^84^ | Ineligible intervention
Tuso, 2014^85^ | Ineligible study design
Van Spall, 2016^86^ | Ineligible publication type
Vieira, 2022^87^ | Ineligible study design
Weisman, 2012^88^ | Ineligible intervention
Wingard, 2017^89^ | Ineligible intervention
Xiao, 2019^90^ | Ineligible study design
Youens, 2019^91^ | Ineligible intervention

1 Abu-Sheasha GA, Bedwani RN, Anwar MM, Cost-effectiveness analysis of three methods of surgical-site infection surveillance: Less is more. American Journal of Infection Control. 2020;48(10):1220–1224.32067812
2 Adams HS, Staten RR, Coty M- B. Initiating Telephone Follow Up After Hospital Discharge From an Inpatient Psychiatric Setting to Reduce Recidivism. Journal of Psychosocial Nursing & Mental Health Services. 2020;58(5):25–31.
3 Ahc M. Interactive Post-discharge Calls Improve Outcomes, Save Time for Case Managers. Hospital Case Management. 2018;26(5).
4 Bashir B, Schneider D, Naglak MC, Evaluation of prediction strategy and care coordination for COPD readmissions. Hospital practice (1995) Hospital practice. 2016;44(3):123–8.27391991
5 Botha UA, Koen L, Mazinu M, Brief Report: A Randomized Control Trial Assessing the Influence of a Telephone-based Intervention on Readmissions for Patients with Severe Mental Illness in a Developing Country. Community Mental Health Journal. 2018;54(2):197–203.27900649
6 Brearly TW, Goodman CS, Haynes C, Improvement of postinpatient psychiatric follow-up for veterans using telehealth. American Journal of Health-System Pharmacy. 2020;77(4):288–294.32031208
7 Cawthon C, Walia S, Osborn CY, Improving care transitions: the patient perspective. Journal of Health Communication. 2012;17 Suppl 3:312–24.23030579
8 Chan B, Goldman L, Sarkar U, The Effect of a Care Transition Intervention on the Patient Experience of Older Multi-Lingual Adults in the Safety Net: Results of a Randomized Controlled Trial. JGIM: Journal of General Internal Medicine. 2015;30(12):1788–1794.25986136
9 Charles L, Jensen L, Torti JMI, Improving transitions from acute care to home among complex older adults using the LACE Index and care coordination. BMJ Open Quality. 2020;9(2):06.
10 Chen C, Li X, Sun L, Post-discharge short message service improves short-term clinical outcome and self-care behaviour in chronic heart failure. ESC heart failure. 2019;6(1):164–173.30478888
11 Choudhury J, Perrio S, Scobell M, Proactive care post-discharge to reduce 30 day readmissions to hospital. International Journal of Risk & Safety in Medicine. 2022;33(S1):S41–S45.35871366
12 Christy S, Sin B, Gim S. Impact of an Integrated Pharmacy Transitions of Care Pilot Program in an Urban Hospital. Journal of Pharmacy Practice. 2016;29(5):490–4.25744762
13 Costantino ME, Frey B, Hall B, The influence of a postdischarge intervention on reducing hospital readmissions in a Medicare population. Population Health Management. 2013;16(5):310–6.23537154
14 Crannage AJ, Hennessey EK, Challen LM, Implementation of a Discharge Education Program to Improve Transitions of Care for Patients at High Risk of Medication Errors. Annals of Pharmacotherapy. 2020;54(6):561–566.31868004
15 Dichmann Sorknaes A. The Effect of Tele-Consultation Between a Hospital-Based Nurse and a COPD Patient. Studies in Health Technology & Informatics. 2016;225:883–4.27332391
16 Donze J, John G, Genne D, Effects of a Multimodal Transitional Care Intervention in Patients at High Risk of Readmission: The TARGET-READ Randomized Clinical Trial. JAMA Internal Medicine. 2023;01:01.
17 Elmose Mols R, Hald M, Sønderby Vistisen H, Nurse-led Motivational Telephone Follow-up After Same-day Percutaneous Coronary Intervention Reduces Readmission and Contacts to General Practice. Journal of Cardiovascular Nursing. 2019;34(3):222–230.30789491
18 Fera T, Anderson C, Kanel KT, Role of a care transition pharmacist in a primary care resource center. American Journal of Health-System Pharmacy. 2014;71(18):1585–90.25174019
19 Freburger JK, Pastva AM, Coleman SW, Skilled Nursing and Inpatient Rehabilitation Facility Use by Medicare Fee-for-Service Beneficiaries Discharged Home After a Stroke: Findings From the COMPASS Trial. Archives of Physical Medicine & Rehabilitation. 2022;103(5):882–890.e2.34740596
20 Gaines-Dillard N. Nurse led telephone follow-up improves satisfaction in motorcycle trauma patients. Journal of Trauma Nursing. 2015;22(2):71–7.25768962
21 Gamez-Lopez AL, Bonilla-Palomas JL, Anguita-Sanchez M, [Effects of three different disease management programs on outcomes in patients hospitalized with heart failure: a randomized trial]. Medicina Clinica. 2012;138(5):192–8.21605879
22 Gesell SB, Bushnell CD, Jones SB, Implementation of a billable transitional care model for stroke patients: the COMPASS study. BMC Health Services Research. 2019;19(1):978.31856808
23 Goldman LE, Sarkar U, Kessell E, Support from hospital to home for elders: a randomized trial. Annals of Internal Medicine. 2014;161(7):472–81.25285540
24 Hamar B, Rula EY, Wells AR, Impact of a scalable care transitions program for readmission avoidance. American Journal of Managed Care. 2016;22(1):28–34.26799122
25 Hamar GB, Coberley C, Pope JE, Effect of post-hospital discharge telephonic intervention on hospital readmissions in a privately insured population in Australia. Australian Health Review. 2018;42(3):241–247.28390471
26 Hani N, Zachariah S, Thomas D, Pharmacist-led heart failure patient focus group using mobile apps-based intervention mix. Journal of Pharmaceutical Health Services Research. 2021;12(1):30–34.
27 Hervieu-Begue M, Jacquin A, Osseby GV, The role of the clinical nurse within a combined stroke and telefibrinolysis network: The G5 pilot study in Burgundy, France. European Research in Telemedicine. 2013;2(1):11–15.
28 Hodalova S, Moore S, Dowds J, Feasibility of Telephone Follow-Up after Critical Care Discharge. Medical Sciences. 2020;8(1):14.32168800
29 Hoyer EH, Brotman DJ, Apfel A, Improving Outcomes After Hospitalization: A Prospective Observational Multicenter Evaluation of Care Coordination Strategies for Reducing 30-Day Readmissions to Maryland Hospitals. Journal of General Internal Medicine. 2018;33(5):621–627.29181790
30 Iacoviello M, Pede S, Aspromonte N, [The APULIA HF multicenter study: efficacy of a management protocol shared between hospital and territorial health services for acute decompensated heart failure patients]. Giornale Italiano di Cardiologia. 2017;18(2):150–158.28398368
31 Irewall A- L, Ögren J, Bergström L, Nurse-led, telephone-based secondary preventive follow-up benefits stroke/TIA patients with low education: a randomized controlled trial sub-study. Trials [Electronic Resource]. 2019;20(1):52.30646948
32 Jahn P, Kuss O, Schmidt H, Improvement of pain-related self-management for cancer patients through a modular transitional nursing intervention: a cluster-randomized multicenter trial. Pain. 2014;155(4):746–754.24434732
33 Jalal ZSMA, Smith F, Taylor D, Impact of pharmacy care upon adherence to cardiovascular medicines: A feasibility pilot controlled trial. European Journal of Hospital Pharmacy. 2016;23(5).
34 Jennings JH, Thavarajah K, Mendez MP, Predischarge bundle for patients with acute exacerbations of COPD to reduce readmissions and ED visits: a randomized controlled trial. Chest. 2015;147(5):1227–1234.25940250
35 Jenq GY, Doyle MM, Belton BM, Quasi-Experimental Evaluation of the Effectiveness of a Large-Scale Readmission Reduction Program. JAMA Internal Medicine. 2016;176(5):681–90.27065180
36 Jones CD, Anthony A, Klein MD, The effect of a pharmacist-led multidisciplinary transitions-of-care pilot for patients at high risk of readmission. Journal of the American Pharmacists Association: JAPhA. 2018;58(5):554–560.30017370
37 Kansagara D, Ramsay RS, Labby D, Post-discharge intervention in vulnerable, chronically ill patients. Journal of Hospital Medicine (Online). 2012;7(2):124–30.
38 Kassymova G, Sydsjö G, Borendal Wodlin N, The Effect of Follow-Up Contact on Recovery after Benign Hysterectomy: A Randomized, Single-Blinded, Four-Arm, Controlled Multicenter Trial. Journal of Women's Health. 2021;30(6):872–881.
39 Kassymova G, Sydsjö G, Wodlin NB, Effect of nurse-led telephone follow-up on postoperative symptoms and analgesics consumption after benign hysterectomy: a randomized, single-blinded, four-arm, controlled multicenter trial. Archives of Gynecology and Obstetrics. 2023;307(2):459–471.36050542
40 Kilcup M, Schultz D, Carlson J, Postdischarge pharmacist medication reconciliation: impact on readmission rates and financial savings. Journal of the American Pharmacists Association: JAPhA. 2013;53(1):78–84.23636160
41 Kirkham HS, Clark BL, Paynter J, The effect of a collaborative pharmacist-hospital care transition program on the likelihood of 30-day readmission. American Journal of Health-System Pharmacy. 2014;71(9):739–45.24733137
42 Kripalani S, Chen G, Ciampa P, A transition care coordinator model reduces hospital readmissions and costs. Contemporary Clinical Trials. 2019;81:55–61.31029692
43 Lavesen M, Ladelund S, Frederiksen AJ, Nurse-initiated telephone follow-up on patients with chronic obstructive pulmonary disease improves patient empowerment, but cannot prevent readmissions. Danish Medical Journal. 2016;63(10).
44 Lee L, Eustache J, Tran-McCaslin M, North American multicentre evaluation of a same-day discharge protocol for minimally invasive colorectal surgery using mHealth or telephone remote post-discharge monitoring. Surgical Endoscopy. 2022;36(12):9335–9344.35419638
45 Lindegaard Pedersen J, Pedersen P, Damsgaard E. Nutritional follow-up after discharge prevents readmission to hospital - A randomized clinical trial. Journal of Nutrition, Health & Aging. 2017;21(1):75–82.27999853
46 Lisby M, Klingenberg M, Ahrensberg JM, Clinical impact of a comprehensive nurse-led discharge intervention on patients being discharged home from an acute medical unit: Randomised controlled trial. International Journal of Nursing Studies. 2019;100:103411.31629207
47 Liu Y, Wen Y, Yu G. Analysis on effect of telephone follow up care for insulin patients after discharge. Chinese Nursing Research. 2013;27(10C):3443–3444.
48 Löser C, Fröhlich A, Poortinga S, Telephone follow-up for monitoring of complications and boosting patient satisfaction after inpatient dermatosurgery: a prospective two-center study. JDDG - Journal of the German Society of Dermatology. 2022;20(1):121–127.
49 March KL, Peters MJ, Finch CK, Pharmacist Transition-of-Care Services Improve Patient Satisfaction and Decrease Hospital Readmissions. Journal of Pharmacy Practice. 2022;35(1):86–93.32945206
50 Marcus P, Hautala K, Allaudeen N. An Initiative to Change Inpatient Practice: Leveraging the Patient Medical Home for Postdischarge Follow-Up. Joint Commission Journal on Quality & Patient Safety. 2018;44(2):101–106.29389458
51 Matarazzo BB, Forster JE, Hostetter TA, Efficacy of the home-based Mental Health Evaluation (HOME) program for engaging patients in care after hospitalization. Psychiatric Services. 2019;70(12):1094–1100.31451065
52 Miller DA, Schaper AM. Implementation of a follow-up telephone call process for patients at high risk for readmission. Journal of Nursing Care Quality. 2015;30(1):63–70.24844916
53 Miller DE, Roane TE, McLin KD. Reduction of 30-Day Hospital Readmissions After Patient-centric Telephonic Medication Therapy Management Services. Hospital Pharmacy. 2016;51(11):907–914.28057950
54 Monkong S, Krairit O, Ngamkala T, Transitional care for older people from hospital to home: a best practice implementation project. JBI Evidence Synthesis. 2020;18(2):357–367.32229738
55 Montero AJ, Stevenson J, Guthrie AE, Reducing Unplanned Medical Oncology Readmissions by Improving Outpatient Care Transitions: A Process Improvement Project at the Cleveland Clinic. Journal of Oncology Practice. 2016;12(5):478–e602.
56 Nguyen AT, Wisniewski J, Leang DW, Effect of the population health inpatient Medicare Advantage pharmacist intervention on hospital readmissions: A quasi-experimental controlled study. Journal of Managed Care & Specialty Pharmacy. 2023;29(3):266–275.36840959
57 Nguyen PA, Enwere E, Gautreaux S, Impact of a pharmacy-driven transitions-of-care program on postdischarge healthcare utilization at a national comprehensive cancer center. American Journal of Health-System Pharmacy. 2018;75(18):1386–1393.30065061
58 Noel K, Messina C, Hou W, Tele-transitions of care (TTOC): a 12-month, randomized controlled trial evaluating the use of Telehealth to achieve triple aim objectives. BMC Family Practice. 2020;21(1):27.32033535
59 O'Reilly EA, Kuszmaul AK, Carter AM, Impact of a transitions of care pilot service established by pharmacy residents within an academic medical center. Journal of the American Pharmacists Association: JAPhA. 2020;60(1):87–92.e2.31735651
60 Odeh M, Scullin C, Fleming G, Ensuring continuity of patient care across the healthcare interface: Telephone follow-up post-hospitalization. British Journal of Clinical Pharmacology. 2019;85(3):616–625.30675742
61 Ota KS, Beutler DS, Gerkin RD, Physician-directed heart failure transitional care program: a retrospective case review. Journal of Clinical Medicine Research. 2013;5(5):335–42.23976905
62 Parodi M, Feeley B, Sanchez M. Impact of a pharmacist-driven transitions of care clinic for a multisite integrated delivery network. American Journal of Health-System Pharmacy. 2022;79(11):844–851.35084448
63 Phatak A, Prusi R, Ward B, Impact of pharmacist involvement in the transitional care of high-risk patients through medication reconciliation, medication education, and postdischarge call-backs (IPITCH Study). Journal of Hospital Medicine (Online). 2016;11(1):39–44.
64 Phillip A, Rossi G, DeSilva R. Stopping the Revolving Door: Reducing 30-Day Psychiatric Readmissions With Post-discharge Telephone Calls. Cureus. 2022;14(1):e21174.35070574
65 Rasmussen LF, Barat I, Riis AH, Effects of a transitional care intervention on readmission among older medical inpatients: a quasi-experimental study. European Geriatric Medicine. 2023;14(1):131–144.36564644
66 Rice YB, Barnes CA, Rastogi R, Tackling 30-Day, All-Cause Readmissions with a Patient-Centered Transitional Care Bundle. Population Health Management. 2016;19(1):56–62.25919315
67 Rinfret S, Rodés-Cabau J, Bagur R, Telephone contact to improve adherence to dual antiplatelet therapy after drug-eluting stent implantation. Heart. 2013;99(8):562–569.23434769
68 Ritchie CS, Houston TK, Richman JS, The E-Coach technology-assisted care transition system: a pragmatic randomized trial. Translational Behavioral Medicine. 2016;6(3):428–37.27339715
69 Ross SY, Roberts S, Taggart H, Stroke Transitions of Care. MEDSURG Nursing. 2017;26(2):119–23.30304593
70 Salmany SS, Ratrout L, Amireh A, The impact of pharmacist telephone calls after discharge on satisfaction of oncology patients: A randomized controlled study. Journal of Oncology Pharmacy Practice. 2018;24(5):359–364.28509614
71 Seto E, Ross H, Tibbles A, A Mobile Phone-Based Telemonitoring Program for Heart Failure Patients After an Incidence of Acute Decompensation (Medly-AID): Protocol for a Randomized Controlled Trial. JMIR Research Protocols. 2020;9(1):e15753.32012116
72 Shah SS, Gvozdanovic A, Knight M, Mobile App-Based Remote Patient Monitoring in Acute Medical Conditions: Prospective Feasibility Study Exploring Digital Health Solutions on Clinical Workload During the COVID Crisis. JMIR Formative Research. 2021;5(1):e23190.33400675
73 Shalaby R, Vuong W, Eboreime E, Patients' Expectations and Experiences With a Mental Health-Focused Supportive Text Messaging Program: Mixed Methods Evaluation. JMIR Formative Research. 2022;6(1):e33438.35014972
74 Shaver A, Morano M, Pogodzinski J, Impact of a community pharmacy transitions-of-care program on 30-day readmission. Journal of the American Pharmacists Association: JAPhA. 2019;59(2):202–209.30552052
75 Shepherd MR, Thomas D, Herald M, Evaluation of a Pharmacist-Managed Heart Failure Education Project. Journal of Pharmacy Technology. 2015;31(3):120–126.
76 Sides EG, Zimmer LO, Wilson L, Medication coaching program for patients with minor stroke or TIA: a pilot study. BMC Public Health. 2012;12:549.22830539
77 Simpson M. A Quality Improvement Plan to Reduce 30-Day Readmissions of Heart Failure Patients. Journal of Nursing Care Quality. 2014;29(3):280–286.24378289
78 Smith A, Hansen J, Colvard M. Impact of a pharmacist-led substance use disorder transitions of care clinic on postdischarge medication treatment retention. Journal of Substance Abuse Treatment. 2021;130.
79 Sutton K, Phelps P. Structured Telephonic Consultation to Decrease COPD 30-Day Readmissions. MEDSURG Nursing. 2021;30(6):377–395.
80 Szöts K, Konradsen H, Solgaard S, Telephone Follow-Up by Nurse After Total Knee Arthroplasty. Orthopaedic Nursing. 2016;35(6):411–420.27851679
81 Tedesco GW, McConaha JL, Skomo ML, A Pharmacist’s Impact on 30-Day Readmission Rates When Compared to the Current Standard of Care Within a Patient-Centered Medical Home: A Pilot Study. Journal of Pharmacy Practice. 2016;29(4):368–73.25634012
82 Trang J, Martinez A, Aslam S, Original article: Pharmacist advancement of transitions of care to home (PATCH) service. Hospital Pharmacy. 2015;50(11):994–1002.27621507
83 Turan Kavradim S, Canli Ozer Z. The effect of education and telephone follow-up intervention based on the Roy Adaptation Model after myocardial infarction: randomised controlled trial. Scandinavian Journal of Caring Sciences. 2020;34(1):247–260.31769891
84 Tuso P, Huynh DN, Garofalo L, The readmission reduction program of Kaiser Permanente Southern California-knowledge transfer and performance improvement. Permanente Journal. 2013;17(3):58–63.24355891
85 Tuso P, Watson HL, Garofalo-Wright L, Complex case conferences associated with reduced hospital admissions for high-risk patients with multiple comorbidities. Permanente Journal. 2014;18(1):38–42.
86 Van Spall H, Ong MK. 2016 - Transition care with telemonitoring did not reduce readmission after hospitalization for heart failure. ACP Journal Club. 2016;164(10):10–10.
87 Vieira A. The Effect of Follow Up Diet Education Calls Post Discharge on Inpatient Heart Failure Readmission Rates. Journal of the Academy of Nutrition & Dietetics. 2022;122(9):A29–A29.
88 Weisman DS, Bashir L, Mehta A, A medical resident post-discharge phone call study. Hospital practice (1995) Hospital practice. 2012;40(2):138–46.22615088
89 Wingard RL, McDougall K, Axley B, Right TraC TM Post-Hospitalization Care Transitions Program to Reduce Readmissions for Hemodialysis Patients. American Journal of Nephrology. 2017;45(6):532–539.28531888
90 Xiao M, St Hill CA, Vacquier M, Retrospective Analysis of the Effect of Postdischarge Telephone Calls by Hospitalists on Improvement of Patient Satisfaction and Readmission Rates. Southern Medical Journal. 2019;112(7):357–362.31282963
91 Youens D, Parsons R, Toye C, The cost-effectiveness of a telephone-based intervention to support caregivers of older people discharged from hospital. BMC Geriatrics. 2019;19(1):68.30832575

## RISK OF BIAS ASSESSMENTS

### RANDOMIZED CONTROLLED TRIALS (ROB-2)

### NONRANDOMIZED COMPARISON STUDIES (ROBINS-I)

## PEER REVIEW COMMENTS AND RESPONSES

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Thank you.
2 | 2 | Yes | Thank you.
3 | 3 | Yes | Thank you.
4 | 4 | Yes | Thank you.
5 | 5 | Yes | Thank you.
6 | 6 | Yes | Thank you.
7 | 7 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
8 | 1 | No | Acknowledge.
9 | 2 | No | Acknowledge.
10 | 3 | Yes - Am surprise that there are many digital / technology facilitated approaches for post-discharge contacts. For example there are emerging examples / studies of electronic symptom monitoring in oncology, surgery that I’ve come across. While this may not have been specified in the definition of post-discharge contacts, I think it is important to consider such types of interventions as a type of touch-points which will likely increase in the near future. I would state that the search strategy may have introduced some bias in this regard. For example, I was unable to find some specific search terms for ‘automated’, ‘symptom monitoring’, etc. in the search strategies. At the minimum, consider including as a limitation. Otherwise I think the synthesis was good. | Thank you. These types of interventions were not a part of the conceptualization of post-discharge contact approaches. We have noted this in the limitations.
11 | 4 | No | Acknowledge.
12 | 6 | No | Acknowledge.
13 | 7 | No | Acknowledge.
Are there any published or unpublished studies that we may have overlooked?
14 | 1 | Yes - not within your search criteria timeframe - but see below for what I believe are some important contextual literature | Thank you and we address this comment below.
15 | 2 | No | Acknowledge.
16 | 3 | No | Acknowledge.
17 | 4 | No | Acknowledge.
18 | 6 | No | Acknowledge.
19 | 7 | Yes - AHRQ Reengineered Discharge https://www.ahrq.gov/patient-safety/settings/hospital/red/toolkit/index.html | This toolkit is now cited in the Background and again in the Discussion sections of the main report, as is the original paper which studied Project RED. Additionally, the toolkit webpage cites a Cochrane review from 2004, and we have included the updated review from 2022 in our citations and background (the Goncalves paper). These references note a small reduction in readmissions when the full toolkit is used.; For the purposes of our review on post-discharge contacts, 10 (and likely 11) of the 12 steps in the toolkit should occur prior to discharge, which we have also highlighted in the discussion.
Additional suggestions or comments can be provided below.
20 | 1 | Overall, I think this report is excellent. Thank you for doing this excellent work.; My note is that, when reading it I was surprised that there was no mention of the works by Coleman’s Care Transitions Intervention or Naylor Home Follow-up program.; Coleman EA, Parry C, Chalmers S, Min S. The Care Transitions Intervention: Results of a Randomized Controlled Trial. Arch Intern Med. 2006;166(17):1822–1828. doi:10.1001/archinte.166.17.1822 17000937; Naylor MD, Brooten D, Campbell R, Comprehensive Discharge Planning and Home Follow-up of Hospitalized Elders: A Randomized Clinical Trial. JAMA. 1999;281(7):613–620. doi:10.1001/jama.281.7.613 10029122; I appreciate why they did not make it into your review (they were not in your time horizon) and, based on the studies that made it in, these may have been too intensive of programs to meet your criteria. Based on this, I have two suggestions for you to consider; 1) If interventions such as these would have not made it into your sample for reasons other than the time horizon, make it more explicit that studies of more comprehensive approaches such as these were excluded.; 2) Consider mentioning these studies in your discussion as examples of more resource-intensive interventions that have been shown to have impact. I appreciate that one might argue that they are now dated enough that the standard of care has changed so that updated studies are needed. However, I would not want your readers to come away with the impression that there are no studies of post-discharge interventions have been shown as being effective. | Thank you for your comments. You are correct that these studies did not make it in due to their publication dates and that the interventions were not conceptually aligned with the type of post-discharge interventions studied here. The focus of this review was on the effectiveness of interventions, in which the majority of the patient contacts are deployed in the post-discharge 7-day window. We state in our discussion that we are focused on a subset of care transition interventions and that more intensive programs have shown positive results. We now cite these studies as historical examples of such programs.
21 | 2 | Overall, the report is outstanding. My recommendations are very minor. | Thank you.
22 | 2 | Pages 12 (line 4) and 20 (line 6) according to Adobe (but says ix and 5 at the bottom left corner of the pages) is incorrect. It was not the “Office of Connected Care”, it was the “Office of Primary Care” that requested this review. | Thank you. We have made that correction.
23 | 2 | Throughout the document you mention medication reconciliation 35 times, but nurses cannot conduct medication reconciliation, we can only conduct medication review due to our scope of practice. I recommend you update the term “medication reconciliation” to “medication review” when referring to post-discharge contact. | Thank you. We have made this change.
24 | 2 | You mention a couple of times how the VHA is the largest integrated health system in the US, but I wonder if it would be valuable to add how many patients we care for, how many facilities we have, etc. to give context. Non-VA folks who may read this likely have no idea how large we are. | Thank you. We have added this detail to the background section.
25 | 3 | With regard to evidence gaps (PICO), would consider specifying older adult patients with multiple chronic conditions as high risk population where there is little or no evidence. With regard to intervention types, I think it would be worthwhile to clarify that multi-contact approaches could be multimodal, specific digital vs non-digital approaches, automated vs in-person. | Thank you. We have added these suggestions to Table 3.
26 | 4 | 1. page ix rows 37 –42 PDC and ED abbreviation is present but unlike other abbreviation it is not identified anywhere prior for APA format. | Thank you.
27 | 4 | 2. page x- section Results of literature-Format of numbers is confusing some are written out some are not? Does this follow APA? | Thank you. Number style follows the rules of the VA ESP program, which asks for all numbers to be numerals. The exception is when a number begins a sentence—then it is spelled out.
28 | 4 | 3. page 9 row 20- typo for the word “documenting” it reads docum2enting. | Thank you; we have corrected this.
29 | 6 | Page x, line 45 - page xi line 31 would be helpful to see information presented in table form, maybe a matrix table that shows study components in one section, outcomes in another, with a list of titles and x’s to show which studies covered what in each area. | Thank you. We have a study characteristics table in the Appendix that gives these details for each included study.
30 | 6 | page xi, line 46–49 is making an assumption about whether the half of studies that did not mention a pre-discharge component actually had this due to it being “standard of care”. If the assumption is not true in a particular setting, the post-discharge contact still could make little difference, but for very different reasons. | We agree with this statement and further contextualize the other reasons why a post-discharge contact as defined in this review may not be impactful in the Discussion.
31 | 6 | Line 20 on p. 9 has a superscript in the middle of a word | Thank you.
32 | 6 | page 17 line 15- explains “elevated risk”. In the ES, I assumed this was “elevated risk” for a psychiatric hospitalization, when in fact, this line shows this is not the case. It would be helpful to clarify this sooner. | Thank you. We define “elevated risk” in the Executive Summary.
33 | | Page 11- line 59; Currently, there is no standard post-discharge practice for Veteran patients transitioning back home from VHA hospitals.; This is not completely accurate: Suggest different verbiage.; While VHA requires primary care Patient Aligned Care Teams (PACT)(2-days) and mental health teams (7-days) to contact Veterans post discharge, there is variability in implementation. | Thank you for the detailed information on VHA PDC implementation for primary care and mental health hospitalizations. We have added this to the background section.