# ABBREVIATIONS TABLE

Abbreviation: Definition
AVR: Aortic valve replacement
CCI: Charlson Comorbidity Index
CI: Confidence interval
CMS: Centers for Medicare and Medicaid Services
COE: Certainty of evidence
COPD: Chronic obstructive pulmonary disorder
ED: Emergency department
EPOC: Effective Practice and Organisation of Care
GRADE: Grading of Recommendations Assessment, Development and Evaluation
KQ: Key question
NR: Not reported
OECD: Organization for Economic Cooperation and Development
OR: Odds ratio
PCM: Pharmacist case manager
PDC: Post-discharge contact
PI: Prediction interval
RCT: Randomized controlled trial
ROB: Risk of bias
TCM: Transitional care management
TEP: Technical expert panel
VHA: Veterans Health Administration