# REFERENCES

1 World Health Organization. Diabetes. https://www.who.int/health-topics/diabetes#tab=tab_1. Accessed February 8, 2022.
2 Centers for Disease Control and Prevention. National Diabetes Statistics Report. U.S. Dept of Health and Human Services, ed. Atlanta, GA: Centers for Disease Control and Prevention; 2020
3 Veterans Health Administration. VHA Directive 1410: Prevention of Amputation in Veterans Everywhere (PAVE) Program. Department of Veterans Affairs, ed. Washington, DC 2017
4 Rothenberg GM, Page J, Stuck R, Spencer C, Kaplan L, Gordon I. Remote Temperature Monitoring of the Diabetic Foot: From Research to Practice. Fed Pract. 2020;37(3):114–124.32317847
5 Diabetic Foot Ulcer An Update. Singapore: Springer; 2021.
6 Brennan MB, Hess TM, Bartle B, . Diabetic foot ulcer severity predicts mortality among veterans with type 2 diabetes. Journal of Diabetes and its Complications. 2017;31(3):56–561.
7 Snyder RJ, Hanft JR. Diabetic foot ulcers - Effects on quality of life, costs, and mortality and the role of standard wound care and advanced-care therapies in healing: A review. Ostomy Wound Management. 2009;55(11):28–38.19934461
8 Whiting P, Savovic J, Higgins JPT, . ROBIS: A new tool to assess risk of bias in systematic reviews was developed. Journal of Clinical Epidemiology. 2016;69:225–234.26092286
9 Pencina MJ, D’Agostino RB, Sr. Evaluating Discrimination of Risk Prediction Models: The C Statistic. JAMA. 2015;314(10):1063–1064.26348755
10 Moons KG, Altman DG, Reitsma JB, . Transparent Reporting of a multivariable prediction model for Individual Prognosis or Diagnosis (TRIPOD): explanation and elaboration. Ann Intern Med. 2015;162(1):W1–73.25560730
11 Crawford F, Chappell FM, Lewsey J, . Risk assessments and structured care interventions for prevention of foot ulceration in diabetes: development and validation of a prognostic model. Health Technol Assess. 2020;24(62):1–198.
12 Bus SA, van Deursen RW, Armstrong DG, . Footwear and offloading interventions to prevent and heal foot ulcers and reduce plantar pressure in patients with diabetes: a systematic review. Diabetes Metab Res Rev. 2016;32 Suppl 1:99–118.26342178
13 Hunt DL. Diabetes: foot ulcers and amputations. BMJ Clin Evid. 2011;2011.
14 Bus SA, Valk GD, van Deursen RW, . The effectiveness of footwear and offloading interventions to prevent and heal foot ulcers and reduce plantar pressure in diabetes: a systematic review. Diabetes Metab Res Rev. 2008;24 Suppl 1:S162–180.18442178
15 Steed DL, Attinger C, Colaizzi T, . Guidelines for the treatment of diabetic ulcers. Wound Repair Regen. 2006;14(6):680–692.17199833
16 Beulens JWJ, Yauw JS, Elders PJM, . Prognostic models for predicting the risk of foot ulcer or amputation in people with type 2 diabetes: a systematic review and external validation study. Diabetologia. 2021;64(7):1550–1562.33904946
17 Monteiro-Soares M, Boyko EJ, Ribeiro J, Ribeiro I, Dinis-Ribeiro M. Risk stratification systems for diabetic foot ulcers: a systematic review. Diabetologia. 2011;54(5):1190–1199.21249490
18 Monteiro-Soares M, Boyko EJ, Jeffcoate W, . Diabetic foot ulcer classifications: A critical review. Diabetes Metab Res Rev. 2020;36 Suppl 1:e3272.32176449
19 Fernandez-Torres R, Ruiz-Munoz M, Perez-Panero AJ, Garcia-Romero JC, Gonzalez-Sanchez M. Clinician Assessment Tools for Patients with Diabetic Foot Disease: A Systematic Review. J Clin Med. 2020;9(5):1487.32429068
20 Monteiro-Soares M, Martins-Mendes D, Vaz-Carneiro A, Sampaio S, Dinis-Ribeiro M. Classification systems for lower extremity amputation prediction in subjects with active diabetic foot ulcer: a systematic review and meta-analysis. Diabetes Metab Res Rev. 2014;30(7):610–622.24523130
21 Karthikesalingam A, Holt PJ, Moxey P, Jones KG, Thompson MM, Hinchliffe RJ. A systematic review of scoring systems for diabetic foot ulcers. Diabet Med. 2010;27(5):544–549.20536950
22 van Netten JJ, Raspovic A, Lavery LA, . Prevention of foot ulcers in the at-risk patient with diabetes: a systematic review. Diabetes Metab Res Rev. 2020;36 Suppl 1:e3270.31957213
23 Crawford F, Nicolson DJ, Amanna AE, . Preventing foot ulceration in diabetes: systematic review and meta-analyses of RCT data. Diabetologia. 2020;63(1):49–64.31773194
24 van Netten JJ, Price PE, Lavery LA, . Prevention of foot ulcers in the at-risk patient with diabetes: a systematic review. Diabetes Metab Res Rev. 2016;32 Suppl 1:84–98.26340966
25 Healy A, Naemi R, Chockalingam N. The effectiveness of footwear as an intervention to prevent or to reduce biomechanical risk factors associated with diabetic foot ulceration: a systematic review. J Diabetes Complications. 2013;27(4):391–400.23643441
26 Paton J, Bruce G, Jones R, Stenhouse E. Effectiveness of insoles used for the prevention of ulceration in the neuropathic diabetic foot: a systematic review. J Diabetes Complications. 2011;25(1):52–62.19854075
27 O’Meara S, Cullum N, Majid M, Sheldon T. Systematic reviews of wound care management: (3) antimicrobial agents for chronic wounds; (4) diabetic foot ulceration. Health Technol Assess. 2000;4(21):1–237.
28 Alahakoon C, Fernando M, Galappaththy C, . Meta-analyses of randomized controlled trials reporting the effect of home foot temperature monitoring, patient education or offloading footwear on the incidence of diabetes-related foot ulcers. Diabet Med. 2020;37(8):1266–1279.32426872
29 Heuch L, Streak Gomersall J. Effectiveness of offloading methods in preventing primary diabetic foot ulcers in adults with diabetes: a systematic review. JBI Database System Rev Implement Rep. 2016;14(7):236–265.
30 Arad Y, Fonseca V, Peters A, Vinik A. Beyond the monofilament for the insensate diabetic foot: a systematic review of randomized trials to prevent the occurrence of plantar foot ulcers in patients with diabetes. Diabetes Care. 2011;34(4):1041–1046.21447666
31 Hingorani A, LaMuraglia GM, Henke P, . The management of diabetic foot: A clinical practice guideline by the Society for Vascular Surgery in collaboration with the American Podiatric Medical Association and the Society for Vascular Medicine. J Vasc Surg. 2016;63(2 Suppl):3S–21S.26804367
32 Jarl G, Lundqvist LO. Adherence to wearing therapeutic shoes among people with diabetes: a systematic review and reflections. Patient Prefer Adherence. 2016;10:1521–1528.27540284
33 Singh N, Armstrong DG, Lipsky BA. Preventing foot ulcers in patients with diabetes. JAMA. 2005;293(2):217–228.15644549
34 Mason J, O’Keeffe C, McIntosh A, Hutchinson A, Booth A, Young RJ. A systematic review of foot ulcer in patients with Type 2 diabetes mellitus. I: prevention. Diabet Med. 1999;16(10):801–812.10547206
35 Lazzarini PA, Jarl G, Gooday C, . Effectiveness of offloading interventions to heal foot ulcers in persons with diabetes: a systematic review. Diabetes Metab Res Rev. 2020;36 Suppl 1:e3275.32176438
36 Healy A, Naemi R, Chockalingam N. The effectiveness of footwear and other removable off-loading devices in the treatment of diabetic foot ulcers: a systematic review. Curr Diabetes Rev. 2014;10(4):215–230.25245020
37 Elraiyah T, Prutsky G, Domecq JP, . A systematic review and meta-analysis of off-loading methods for diabetic foot ulcers. J Vasc Surg. 2016;63(2 Suppl):59S–68S e51-52.26804369
38 Healy A, Farmer S, Pandyan A, Chockalingam N. A systematic review of randomised controlled trials assessing effectiveness of prosthetic and orthotic interventions. PLoS One. 2018;13(3):e0192094.29538382
39 Health Quality Ontario. Fibreglass Total Contact Casting, Removable Cast Walkers, and Irremovable Cast Walkers to Treat Diabetic Neuropathic Foot Ulcers: A Health Technology Assessment. Ontario health technology assessment series. 2017;17(12):1–124.
40 Snyder RJ, Frykberg RG, Rogers LC, . The management of diabetic foot ulcers through optimal off-loading: building consensus guidelines and practical recommendations to improve outcomes. J Am Podiatr Med Assoc. 2014;104(6):555–567.25514266
41 Lin C, Liu J, Sun H. Risk factors for lower extremity amputation in patients with diabetic foot ulcers: A meta-analysis. PloS one. 2020;15(9):e0239236.32936828
42 Boyko EJ, Ahroni JH, Cohen V, Nelson KM, Heagerty PJ. Prediction of diabetic foot ulcer occurrence using commonly available clinical information: the Seattle Diabetic Foot Study. Diabetes Care. 2006;29(6):1202–1207.16731996
43 Martins-Mendes D, Monteiro-Soares M, Boyko EJ, . The independent contribution of diabetic foot ulcer on lower extremity amputation and mortality risk. J Diabetes Complications. 2014;28(5):632–638.24877985
44 Lazzarini PA, Ng V, Kinnear EM, . The Queensland high risk foot form (QHRFF) - is it a reliable and valid clinical research tool for foot disease? J Foot Ankle Res. 2014;7(1):7.24468080
45 Crawford F, Cezard G, Chappell FM, . A systematic review and individual patient data meta-analysis of prognostic factors for foot ulceration in people with diabetes: the international research collaboration for the prediction of diabetic foot ulcerations (PODUS). Health technology assessment (Winchester, England). 2015;19(57):1–210.
46 Chappell FM, Crawford F, Horne M, . Development and validation of a clinical prediction rule for development of diabetic foot ulceration: an analysis of data from five cohort studies. BMJ open diabetes research & care. 2021;9(1).
47 Chuan F, Tang K, Jiang P, Zhou B, He X. Reliability and validity of the perfusion, extent, depth, infection and sensation (PEDIS) classification system and score in patients with diabetic foot ulcer. PLoS One. 2015;10(4):e0124739.25875097
48 Ince P, Abbas ZG, Lutale JK, . Use of the SINBAD classification system and score in comparing outcome of foot ulcer management on three continents. Diabetes Care. 2008;31(5):964–967.18299441
49 Kerr M, Barron E, Chadwick P, . The cost of diabetic foot ulcers and amputations to the National Health Service in England. Diabet Med. 2019;36(8):995–1002.31004370
50 Department of Veterans Affairs. Health Equity podcast #6: Preventing diabetic foot ulcers [Internet]; 2022. Podcast. Available from: https://blogs.va.gov/VAntage/99531/health-equity-podcast-6-preventing-diabetic-foot-ulcers/
51 Senneville E, Lipsky BA, Abbas ZG, . Diagnosis of infection in the foot in diabetes: a systematic review. Diabetes/metabolism research and reviews. 2020;36 Suppl 1:e3281.32176440